# Appendix A Summary of Lesions in Rats and Mice

Table A-1 Summary of the Incidence of Nonneoplastic Lesions in Male Rats in the Three-month Dermal Study of OTNE^a^

| Untreated Control | Vehicle Control | 6.25% | 12.5% | 25% | 50% | 100%
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10 | 10
Survivors
Terminal euthanasia | 10 | 10 | 10 | 10 | 10 | 10 | 10
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Esophagus | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Intestine large, cecum | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Intestine large, colon | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Intestine large, rectum | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Intestine small, duodenum | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Intestine small, ileum | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Intestine small, jejunum | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Liver | (10) | (10) | (10) | (10) | (10) | (10) | (10)
Inflammation, chronic | 1 (10%) | – | – | – | – | – | –
Oral mucosa | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Pancreas | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Acinus, atrophy | – | 1 (10%) | – | – | – | – | –
Salivary glands | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Stomach, forestomach | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Stomach, glandular | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Tongue | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Cardiovascular System
Blood vessel | (10) | (10) | (0) | (0) | (0) | (0) | (9)
Heart | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Cardiomyopathy | 1 (10%) | 1 (10%) | – | – | – | – | 1 (10%)
Infiltration cellular, histiocyte, focal | – | – | – | – | – | – | 1 (10%)
Inflammation, chronic | 1 (10%) | – | – | – | – | – | –
Endocrine System
Adrenal cortex | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Adrenal medulla | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Parathyroid gland | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Pituitary gland | (9) | (8) | (0) | (0) | (0) | (0) | (9)
Thyroid gland | (10) | (10) | (0) | (0) | (0) | (0) | (10)
General Body System
None | – | – | – | – | – | – | –
Genital System
Epididymis | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Preputial gland | (9) | (8) | (0) | (0) | (0) | (0) | (9)
Inflammation, chronic | 2 (22%) | – | – | – | – | – | 1 (11%)
Prostate | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Seminal vesicle | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Testes | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Hematopoietic System
Bone marrow | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Lymph node | (0) | (0) | (0) | (0) | (0) | (0) | (1)
Mediastinal, hyperplasia, lymphoid, diffuse | – | – | – | – | – | – | 1 (100%)
Lymph node, mandibular | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Lymph node, mesenteric | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Infiltration cellular, histiocyte | 1 (10%) | 1 (10%) | – | – | – | – | –
Spleen | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Thymus | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Integumentary System
Mammary gland | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Skin | (10) | (10) | (10) | (10) | (10) | (10) | (10)
Hyperplasia | – | – | 1 (10%) | – | – | – | –
Inflammation | – | – | 1 (10%) | – | – | – | –
Skin, site of application | (10) | (10) | (10) | (10) | (10) | (10) | (10)
Hyperkeratosis | – | – | 1 (10%) | 3 (30%) | 4 (40%) | 5 (50%) | 8 (80%)
Hyperplasia | – | – | 2 (20%) | 4 (40%) | 5 (50%) | 8 (80%) | 10 (100%)
Inflammation | – | – | – | – | – | – | 1 (10%)
Musculoskeletal System
Bone | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Nervous System
Brain | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Respiratory System
Larynx | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Inflammation, neutrophil | 1 (10%) | – | – | – | – | – | –
Lung | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Hemorrhage | 1 (10%) | – | – | – | – | – | –
Infiltration cellular, histiocyte | – | – | – | – | – | – | 1 (10%)
Inflammation, chronic | 4 (40%) | 5 (50%) | – | – | – | – | 5 (50%)
Interstitium, inflammation, focal | 2 (20%) | 1 (10%) | – | – | – | – | –
Nose | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Trachea | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Special Senses System
Eye | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Harderian gland | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Urinary System
Kidney | (10) | (10) | (10) | (10) | (10) | (10) | (10)
Nephropathy | 10 (100%) | 8 (80%) | 9 (90%) | 10 (100%) | 10 (100%) | 10 (100%) | 10 (100%)
Renal tubule, casts | 3 (30%) | – | 1 (10%) | 1 (10%) | – | 1 (10%) | –
Urinary bladder | (10) | (10) | (0) | (0) | (0) | (0) | (10)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.

Table A-2 Summary of the Incidence of Nonneoplastic Lesions in Female Rats in the Three-month Dermal Study of OTNE^a^

| Untreated Control | Vehicle Control | 6.25% | 12.5% | 25% | 50% | 100%
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10 | 10
Survivors
Terminal euthanasia | 10 | 10 | 10 | 10 | 10 | 10 | 10
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Esophagus | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Intestine large, cecum | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Intestine large, colon | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Intestine large, rectum | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Intestine small, duodenum | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Intestine small, ileum | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Intestine small, jejunum | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Liver | (10) | (10) | (10) | (10) | (10) | (10) | (10)
Inflammation, chronic | 6 (60%) | 5 (50%) | 7 (70%) | 9 (90%) | 5 (50%) | 5 (50%) | 5 (50%)
Oral mucosa | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Pancreas | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Salivary glands | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Stomach, forestomach | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Stomach, glandular | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Tongue | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Cardiovascular System
Blood vessel | (9) | (10) | (0) | (0) | (0) | (0) | (10)
Heart | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Cardiomyopathy | – | 1 (10%) | – | – | – | – | –
Endocrine System
Adrenal cortex | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Adrenal medulla | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Parathyroid gland | (9) | (10) | (0) | (0) | (0) | (0) | (10)
Pituitary gland | (7) | (4) | (0) | (0) | (0) | (0) | (10)
Pars distalis, cyst, multiple, focal | 1 (14%) | – | – | – | – | – | –
Thyroid gland | (10) | (10) | (0) | (0) | (0) | (0) | (10)
General Body System
None | – | – | – | – | – | – | –
Genital System
Clitoral gland | (9) | (10) | (0) | (0) | (0) | (0) | (10)
Inflammation, chronic | – | 1 (10%) | – | – | – | – | –
Ovary | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Uterus | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Hematopoietic System
Bone marrow | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Lymph node | (0) | (1) | (0) | (0) | (0) | (0) | (0)
Iliac, hyperplasia, diffuse | – | 1 (100%) | – | – | – | – | –
Lymph node, mandibular | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Lymph node, mesenteric | (9) | (10) | (0) | (0) | (0) | (0) | (10)
Infiltration cellular, histiocyte | 4 (44%) | 6 (60%) | – | – | – | – | 5 (50%)
Spleen | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Thymus | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Integumentary System
Mammary gland | (8) | (10) | (0) | (0) | (0) | (0) | (10)
Skin | (10) | (10) | (10) | (10) | (10) | (10) | (10)
Skin, site of application | (10) | (10) | (10) | (10) | (10) | (10) | (10)
Hyperkeratosis | – | – | – | 4 (40%) | 5 (50%) | 7 (70%) | 7 (70%)
Hyperplasia | – | – | 1 (10%) | 5 (50%) | 7 (70%) | 7 (70%) | 8 (80%)
Dermis, inflammation, suppurative | – | – | – | – | – | – | 1 (10%)
Hair follicle, necrosis | – | – | – | – | – | – | 1 (10%)
Musculoskeletal System
Bone | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Nervous System
Brain | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Respiratory System
Larynx | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Lung | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Infiltration cellular, histiocyte | – | – | – | – | – | – | 1 (10%)
Inflammation, chronic | 2 (20%) | 3 (30%) | – | – | – | – | 1 (10%)
Mineralization | – | 1 (10%) | – | – | – | – | –
Interstitium, inflammation, focal | 3 (30%) | 1 (10%) | – | – | – | – | 1 (10%)
Nose | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Trachea | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Special Senses System
Ear | (1) | (0) | (0) | (0) | (0) | (0) | (1)
Eye | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Harderian gland | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Inflammation, chronic | 3 (30%) | 1 (10%) | – | – | – | – | 3 (30%)
Urinary System
Kidney | (10) | (10) | (10) | (10) | (10) | (10) | (10)
Inflammation, chronic | – | 2 (20%) | – | – | 1 (10%) | – | –
Mineralization | – | 1 (10%) | – | – | 2 (20%) | – | 1 (10%)
Nephropathy | 2 (20%) | 1 (10%) | – | – | – | – | –
Pelvis, inflammation, chronic | – | – | – | – | – | 1 (10%) | –
Urinary bladder | (9) | (9) | (0) | (0) | (0) | (0) | (10)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.

Table A-3 Summary of the Incidence of Neoplasms and Nonneoplastic Lesions in Male Mice in the Three-month Dermal Study of OTNE^a^

| Untreated Control | Vehicle Control | 6.25% | 12.5% | 25% | 50% | 100%
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10 | 10
Survivors
Terminal euthanasia | 10 | 10 | 10 | 10 | 10 | 10 | 10
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Esophagus | (9) | (10) | (0) | (0) | (0) | (0) | (9)
Gallbladder | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Intestine large, cecum | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Intestine large, colon | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Intestine large, rectum | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Intestine small, duodenum | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Intestine small, ileum | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Intestine small, jejunum | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Liver | (10) | (10) | (10) | (10) | (9) | (10) | (10)
Centrilobular, hypertrophy | – | 1 (10%) | – | 2 (20%) | 3 (33%) | – | 4 (40%)
Oral mucosa | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Pancreas | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Salivary glands | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Stomach, forestomach | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Stomach, glandular | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Tongue | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Cardiovascular System
Blood vessel | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Heart | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Endocrine System
Adrenal cortex | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Adrenal medulla | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Parathyroid gland | (9) | (10) | (0) | (0) | (0) | (0) | (10)
Cyst | 1 (11%) | 2 (20%) | – | – | – | – | –
Pituitary gland | (10) | (9) | (0) | (0) | (0) | (0) | (10)
Thyroid gland | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Follicle, degeneration | 1 (10%) | – | – | – | – | – | –
General Body System
None | – | – | – | – | – | – | –
Genital System
Epididymis | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Preputial gland | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Prostate gland | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Seminal vesicle | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Testes | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Hematopoietic System
Bone marrow | (10) | (10) | (10) | (10) | (10) | (10) | (10)
Lymph node, mandibular | (9) | (10) | (0) | (0) | (0) | (0) | (9)
Lymph node, mesenteric | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Spleen | (10) | (10) | (10) | (10) | (9) | (10) | (10)
Thymus | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Integumentary System
Mammary gland | (4) | (4) | (0) | (0) | (0) | (0) | (4)
Skin | (10) | (10) | (10) | (10) | (9) | (10) | (10)
Fibrosis | – | – | – | – | 1 (11%) | 2 (20%) | 5 (50%)
Hyperkeratosis | – | – | – | – | – | 2 (20%) | 5 (50%)
Hyperplasia | – | – | – | 2 (20%) | 4 (44%) | 3 (30%) | 8 (80%)
Inflammation, neutrophil | – | – | – | – | – | – | 1 (10%)
Inflammation, chronic active | – | – | – | 2 (20%) | 4 (44%) | 2 (20%) | 8 (80%)
Epidermis, inflammation, suppurative | – | – | – | – | – | 1 (10%) | 4 (40%)
Hair follicle, hyperplasia | – | – | – | 1 (10%) | – | 1 (10%) | 5 (50%)
Skin, site of application | (10) | (10) | (10) | (10) | (10) | (9) | (10)
Fibrosis | – | – | 4 (40%) | 3 (30%) | 8 (80%) | 8 (89%) | 10 (100%)
Hyperkeratosis | – | – | 2 (20%) | 5 (50%) | 5 (50%) | 8 (89%) | 10 (100%)
Hyperplasia | – | – | 9 (90%) | 10 (100%) | 9 (90%) | 9 (100%) | 10 (100%)
Inflammation, chronic active | – | – | 7 (70%) | 10 (100%) | 9 (90%) | 9 (100%) | 10 (100%)
Epidermis, inflammation, suppurative | – | – | – | – | 1 (10%) | 1 (11%) | 5 (50%)
Hair follicle, hyperplasia | – | – | 3 (30%) | 2 (20%) | 3 (30%) | 7 (78%) | 8 (80%)
Musculoskeletal System
Bone | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Skeletal muscle | (0) | (1) | (0) | (0) | (0) | (0) | (0)
Nervous System
Brain | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Granular cell tumor malignant | – | 1 (10%) | – | – | – | – | –
Respiratory System
Larynx | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Lung | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Nose | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Trachea | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Special Senses System
Eye | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Retina, dysplasia | – | 1 (10%) | – | – | – | – | –
Retrobulbar, inflammation, neutrophil | 1 (10%) | – | – | – | – | – | –
Harderian gland | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Inflammation, neutrophil | – | 2 (20%) | – | – | – | – | 1 (10%)
Inflammation, chronic | – | – | – | – | – | – | 1 (10%)
Urinary System
Kidney | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Inflammation, chronic | – | 1 (10%) | – | – | – | – | –
Urinary bladder | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Neoplasm Summary
Animals with primary neoplasms^b^ | | 1 | – | – | – | – | –
Total primary neoplasms | | 1 | – | – | – | – | –
Total animals with malignant neoplasms | | 1 | – | – | – | – | –
Total malignant neoplasms | | 1 | – | – | – | – | –

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.

^b^ Primary neoplasms: all neoplasms except metastatic neoplasms.

Table A-4 Summary of the Incidence of Nonneoplastic Lesions in Female Mice in the Three-month Dermal Study of OTNE^a^

| Untreated Control | Vehicle Control | 6.25% | 12.5% | 25% | 50% | 100%
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10 | 10
Survivors
Terminal euthanasia | 10 | 10 | 10 | 10 | 10 | 10 | 10
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Esophagus | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Gallbladder | (10) | (9) | (0) | (0) | (0) | (0) | (10)
Intestine large, cecum | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Intestine large, colon | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Intestine large, rectum | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Intestine small, duodenum | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Intestine small, ileum | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Intestine small, jejunum | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Liver | (10) | (10) | (10) | (10) | (10) | (10) | (10)
Oral mucosa | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Pancreas | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Salivary glands | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Stomach, forestomach | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Stomach, glandular | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Tongue | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Cardiovascular System
Blood vessel | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Heart | (10) | (10) | (10) | (10) | (10) | (9) | (10)
Endocrine System
Adrenal cortex | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Adrenal medulla | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Parathyroid gland | (9) | (7) | (0) | (0) | (0) | (0) | (8)
Cyst | – | – | – | – | – | – | 1 (13%)
Pituitary gland | (10) | (10) | (0) | (0) | (0) | (0) | (9)
Thyroid gland | (10) | (10) | (0) | (0) | (0) | (0) | (10)
General Body System
None | – | – | – | – | – | – | –
Genital System
Clitoral gland | (9) | (6) | (0) | (0) | (0) | (0) | (10)
Ovary | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Uterus | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Vagina | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Hematopoietic System
Bone marrow | (10) | (10) | (10) | (10) | (10) | (10) | (10)
Lymph node | (0) | (0) | (0) | (0) | (0) | (0) | (1)
Lymph node, mandibular | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Lymph node, mesenteric | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Spleen | (10) | (10) | (10) | (10) | (10) | (8) | (10)
Thymus | (10) | (10) | (10) | (10) | (10) | (8) | (10)
Atrophy | – | – | – | – | – | – | 2 (20%)
Integumentary System
Mammary gland | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Skin | (10) | (10) | (10) | (10) | (10) | (8) | (10)
Fibrosis | – | – | – | 3 (30%) | – | – | 6 (60%)
Hyperkeratosis | – | – | – | 1 (10%) | – | – | 7 (70%)
Hyperplasia | – | – | 4 (40%) | 3 (30%) | 2 (20%) | 3 (38%) | 10 (100%)
Inflammation, chronic active | – | – | 4 (40%) | 4 (40%) | 2 (20%) | 3 (38%) | 8 (80%)
Ulcer | – | – | – | – | – | – | 1 (10%)
Epidermis, inflammation, suppurative | – | – | – | – | – | – | 8 (80%)
Hair follicle, hyperplasia | – | – | – | – | 1 (10%) | – | 3 (30%)
Skin, site of application | (10) | (10) | (10) | (10) | (10) | (6) | (10)
Fibrosis | – | – | 2 (20%) | 10 (100%) | 10 (100%) | 4 (67%) | 9 (90%)
Hyperkeratosis | – | – | 5 (50%) | 5 (50%) | 10 (100%) | 6 (100%) | 10 (100%)
Hyperplasia | – | – | 10 (100%) | 10 (100%) | 10 (100%) | 6 (100%) | 10 (100%)
Inflammation, chronic active | – | – | 10 (100%) | 10 (100%) | 10 (100%) | 6 (100%) | 10 (100%)
Ulcer | – | 1 (10%) | – | – | – | 1 (17%) | –
Epidermis, inflammation, suppurative | – | – | – | 1 (10%) | 4 (40%) | 4 (67%) | 7 (70%)
Hair follicle, hyperplasia | – | – | 3 (30%) | – | 4 (40%) | 3 (50%) | 10 (100%)
Musculoskeletal System
Bone | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Nervous System
Brain | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Respiratory System
Larynx | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Lung | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Nose | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Trachea | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Special Senses System
Eye | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Retrobulbar, inflammation, neutrophil | – | – | – | – | – | – | 1 (10%)
Harderian gland | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Urinary System
Kidney | (10) | (10) | (0) | (0) | (0) | (0) | (10)
Nephropathy | – | 1 (10%) | – | – | – | – | –
Urinary bladder | (9) | (10) | (0) | (0) | (0) | (0) | (10)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.