# Errata

Errors were identified in the NTP Toxicity Report on Abrasive Blasting Agents (TOX 91). Incorrect supplier information was reported for the five test materials, and detailed information about trade names and bulk material preparation was inadvertently omitted.

In the Materials and Methods on page 8 and in Appendix C on page C-2, the text was revised to identify the correct suppliers and additional information on trade names was included for each blasting agent in the HTML and PDF versions of this report. [September 1, 2022]

In the Materials and Methods and in Appendix C, additional information describing the bulk material preparation of blasting sand was added to the text, including a summary sentence on page 8 and information regarding the bulk material preparation for blasting sand (page C-2), coal slag (page C-4), crushed glass (page C-5), garnet (page C-6), and specular hematite (page C-6). This information was added to the HTML and PDF versions of this report. [September 1, 2022]