# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2378-8992

DOI: https://doi.org/10.22427/NTP-TOX-91

Report Series: NTP Toxicity Report Series

Report Series Number: 91

Official citation: National Toxicology Program (NTP). 2020. NTP technical report on the toxicity studies of abrasive blasting agents administered by inhalation to F344/NTac rats and Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) rats. Research Triangle Park, NC: National Toxicology Program. Toxicity Report 91.