# Peer Review

The draft NTP Technical Report on the Toxicity Studies of Abrasive Blasting Agents Administered by Inhalation to F344/NTac Rats and Sprague Dawley (Hsd:Sprague Dawley^®^ SD^®^) Rats was evaluated by the reviewers listed below. These reviewers served as independent scientists, not as representatives of any institution, company, or governmental agency. In this capacity, reviewers determined if the design and conditions of these NTP studies were appropriate and ensured that this Toxicity Report presents the experimental results and conclusions fully and clearly.

## Peer Reviewers

- Wanda Haschek-Hock, Ph.D.
  Department of Pathobiology
  University of Illinois
  Urbana, Illinois, USA
- Devon Andres, Ph.D.
  Tauri Group
  Bel Air, Maryland, USA