# References

1 Hubbs AF, Minhas NS, Jones W, Greskevitch M, Battelli LA, Porter DW, Goldsmith WT, Frazer D, Landsittel DP, Ma JYC. Comparative pulmonary toxicity of 6 abrasive blasting agents. Toxicol Sci. 2001; 61(1):135–143. 10.1093/toxsci/61.1.135 11294984
2 National Institute for Occupational Safety and Health (NIOSH). Criteria for a recommended standard: Occupational exposure to crystalline silica. Washington, DC: U.S. Department of Health and Human Services, Centers for Disease Control and Prevention, National Institute for Occupational Safety and Health; 1974.
3 National Institute for Occupational Safety and Health (NIOSH). Evaluation of substitute materials for silica sand in abrasive blasting. Cincinnati, OH: U.S. Department of Health and Human Services, Centers for Disease Control and Prevention, National Institute for Occupational Safety and Health; 1998. KTA-Tator Inc., Contract No. 200-95-2946.
4 National Institute for Occupational Safety and Health (NIOSH). Substitute materials for silica sand in abrasive blasting. Washington, DC: U.S. Department of Health and Human Services, Centers for Disease Control and Prevention, National Institute for Occupational Safety and Health; 2001. CDC Publication No. (NIOSH) 2002-100.
5 Porter DW, Hubbs AF, Robinson VA, Battelli LA, Greskevitch M, Barger M, Landsittel D, Jones W, Castranova V. Comparative pulmonary toxicity of blasting sand and five substitute abrasive blasting agents. J Toxicol Environ Health A. 2002; 65(16):1121–1140. 10.1080/152873902760125363 12167212
6 Olson DW. Garnet, industrial. In: US Geological Survey Minerals Yearbook. Reston, VA: U.S. Geological Survey; 2004. p. 291-293.
7 Stettler LE, Salomon RA, Platek SF, Moorman WJ, Clark JC, Krieg EF, Phipps FC. Fibrogenic potentials of coal slags used as abrasive blasting substitutes. J Toxicol Environ Health. 1995; 45(3):349–365. 10.1080/15287399509532001 7609007
8 Stettler L, Donaldson H, Grant G. Chemical composition of coal and other mineral slags. Am Ind Hyg Assoc J. 1982; 43(4):235–238. 10.1080/15298668291409668
9 Paumanok Publications Inc. The U.S. market for blasting abrasives: 1992-1997 analysis. Shoreham, NY: Paumanok Publications Inc.; 1992.
10 Silicosis and Silicate Disease Committee. Diseases associated with exposure to silica and nonfibrous silicate minerals. Arch Pathol Lab Med. 1988; 112(7):673–720. 2838005
11 Myers CE, Hayden C, Morgan J. Clinical experience with silicotuberculosis. Pa Med. 1973; 76(3):60. 4688985
12 Bailey WC, Brown M, Buechner HA, Weill H, Ichinose H, Ziskind M. Silico-mycobacterial disease in sandblasters. Am Rev Respir Dis. 1974; 110(2):115–125. 4137927
13 Sherson D, Lander F. Morbidity of pulmonary tuberculosis among silicotic and nonsilicotic foundry workers in Denmark. J Occup Med. 1990; 32(2):110–113. 2303918
14 Hansink JD. An introduction to abrasives for protective coating removal operations. J Prot Coat Linings. 2000; 17(4):66-73.
15 National Institute for Occupational Safety and Health (NIOSH). National occupational exposure survey (1981-1983), unpublished provisional data as of July 1, 1990. Cincinnati, OH: U.S. Department of Health and Human Services, Centers for Disease Control and Prevention, National Institute for Occupational Safety and Health; 1990.
16 National Institute for Occupational Safety and Health (NIOSH). National occupational exposure survey field guidelines. Cincinnati, OH: U.S. Department of Health and Human Services, Centers for Disease Control and Prevention, National Institute for Occupational Safety and Health; 1988. DHHS (NIOSH) Publication No. 88-106.
17 National Institute for Occupational Safety and Health (NIOSH). National occupational exposure survey sampling methodology. Cincinnati, OH: U.S. Department of Health and Human Services, Centers for Disease Control and Prevention, National Institute for Occupational Safety and Health; 1990.
18 National Institute for Occupational Safety and Health (NIOSH). NIOSH alert: Preventing silicosis and deaths from sandblasting. Washington, DC: U.S. Department of Health and Human Services, Centers for Disease Control and Prevention, National Institute for Occupational Safety and Health; 1992. DHHS (NIOSH) Publication No. 92-102.
19 Code of Federal Regulations (CFR). 29:§1910.1000.
20 National Toxicology Program (NTP). 6th Report of Carcinogens. Summary 1991. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 1991.
21 International Agency for Research on Cancer (IARC). IARC monographs on the evaluation of the carcinogenic risks to humans: Silica, some silicates, coal dust and para-aramid fibrils. Vol. 68. Lyon, France: IARC; 1997.
22 American Conference of Governmental Industrial Hygienists (ACGIH). 2015 TLVs® and BEIs® based on the documentation of the threshold limit values for chemical substances and physical agents & biological exposure indices. Cincinnati, OH: ACGIH; 2015.
23 National Institute for Occupational Safety and Health (NIOSH). Industrial health and safety criteria for abrasive blast cleaning operations. Cincinnati, OH: U.S. Department of Health and Human Services, Centers for Disease Control and Prevention, National Institute for Occupational Safety and Health; 1974. Contract No. HSM 99-72-83. Hew Publication No. (NIOSH) 75-122.
24 Samimi B, Weill H, Ziskind M. Respirable silica dust exposure of sandblasters and associated workers in steel fabrication yards. Arch Environ Health. 1974; 29(2):61–66. 10.1080/00039896.1974.10666534 4365923
25 Ministry of Labour and National Service. Factories Act of 1937 and 1948: Report on the draft blasting (castings and other articles) special regulations. London, UK: Ministry of Labour and National Service, Factory Department; 1949. SI 1949, No. 2225. p. 4331-4335.
26 International Labour Organization (ILO). Encyclopedia of occupational health and safety. Vol. 2. New York, NY: McGraw Hill Book Company, Inc; 1972. p. 1267–1270.
27 MacKay G, Stettler L, Kommineni C, Donaldson H. Fibrogenic potential of slags used as substitutes for sand in abrasive blasting operations. Am Ind Hyg Assoc J. 1980; 41(11):836–842. 10.1080/15298668091425725 7457375
28 Stettler LE, Proctor JE, Platek SF, Carolan RJ, Smith RJ, Donaldson HM. Fibrogenicity and carcinogenic potential of smelter slags used as abrasive blasting substitutes. J Toxicol Environ Health. 1988; 25(1):35–56. 10.1080/15287398809531187 2458479
29 National Institute for Occupational Safety and Health (NIOSH). NIOSH alert: Request for assistance in preventing lead poisoning in construction workers. Cincinnati, OH: U.S. Department of Health and Human Services, Centers for Disease Control and Prevention, National Institute for Occupational Safety and Health; 1992. DHHS (NIOSH) Publication No. 91-116a.
30 Beck BD, Brain JD, Bohannon DE. An in vivo hamster bioassay to assess the toxicity of particulates for the lungs. Toxicol Appl Pharmacol. 1982; 66(1):9–29. 10.1016/0041-008X(82)90057-6 6925426
31 Kavet RI, Brain J, Levens DJ. Characteristics of pulmonary macrophages lavaged from hamsters exposed to iron oxide aerosols. Lab Invest. 1978; 38(3):312. 633855
32 Antonini JM, Murthy GGK, Rogers RA, Albert R, Ulrich GD, Brain JD. Pneumotoxicity and pulmonary clearance of different welding fumes after intratracheal instillation in the rat. Toxicol Appl Pharmacol. 1996; 140(1):188–199. 10.1006/taap.1996.0212 8806885
33 Harding HE. Radiographic and histological appearances of the rat lung after intratracheal injection of rouge (Fe2O3). Br J Ind Med. 1945; 2(1):32-35. 10.1136/oem.2.1.32
34 Vallyathan V, Castranova V, Pack D, Leonard S, Shumaker J, Hubbs AF, Shoemaker DA, Ramsey DM, Pretty JR, McLaurin JL. Freshly fractured quartz inhalation leads to enhanced lung injury and inflammation. Potential role of free radicals. Am J Respir Crit Care Med. 1995; 152(3):1003–1009. 10.1164/ajrccm.152.3.7663775 7663775
35 Vallyathan V, Shi X, Dalal NS, Irr W, Castranova V. Generation of free radicals from freshly fractured silica dust. Am Rev Respir Dis. 1988; 138(5):1213–1219. 10.1164/ajrccm/138.5.1213 2849348
36 Castranova V, Pailes WH, Dalai NS, Miles PR, Bowman L, Vallyathan V, Pack D, Weber KC, Hubbs A, Schwegler-Berry D. Enhanced pulmonary response to the inhalation of freshly fractured silica as compared with aged dust exposure. Appl Occup Environ Hyg. 1996; 11(7):937–941. 10.1080/1047322X.1996.10389993
37 Axelson O, Sjöberg A. Cancer incidence and exposure to iron oxide dust. J Occup Med. 1979; 21(6):419–422. 556421
38 Saffiotti U, Cefis F, Kolb LH. A method for the experimental induction of bronchogenic carcinoma. Cancer Res. 1968; 28(1):104–124. 5635364
39 Nettesheim P, Creasia DA, Mitchell TJ. Carcinogenic and cocarcinogenic effects of inhaled synthetic smog and ferric oxide particles. J Natl Cancer Inst. 1975; 55(1):159–169. 10.1093/jnci/55.1.159 1159809
40 Steinhoff D, Mohr U, Hahnemann S. Carcinogenesis studies with iron oxides. Exp Pathol. 1991; 43(3-4):189–194. 10.1016/S0232-1513(11)80116-7 1797572
41 Teculescu D, Albu A. Pulmonary function in workers inhaling iron oxide dust. Int Arch Arbeitsmed. 1973; 31(2):163–170. 10.1007/BF02178954 4751373
42 Lay JC, Bennett WD, Ghio AJ, Bromberg PA, Costa DL, Kim CS, Koren HS, Devlin RB. Cellular and biochemical response of the human lung after intrapulmonary instillation of ferric oxide particles. Am J Respir Cell Mol Biol. 1999; 20(4):631–642. 10.1165/ajrcmb.20.4.3355 10100994
43 Cox LA Jr. An exposure‐response threshold for lung diseases and lung cancer caused by crystalline silica. Risk Anal. 2011; 31(10):1543–1560. 10.1111/j.1539-6924.2011.01610.x 21477084
44 International Agency for Research on Cancer (IARC). IARC monographs on the evaluation of the carcinogenic risks to humans: Arsenic, metals, fibres, and dusts. Vol. 100c. Lyon, France: IARC; 2012.
45 International Agency for Research on Cancer (IARC). IARC monographs on the evaluation of the carcinogenic risks to humans: Overall evaluations of carcinogenicity: An updating of IARC monographs volumes 1 to 42. Lyon, France: IARC; 1987.
46 International Agency for Research on Cancer (IARC). IARC monographs on the evaluation of the carcinogenic risks to humans: Silica and some silicates. Vol. 42. Lyon, France: IARC; 1987.
47 National Toxicology Program (NTP). 14th Report on Carcinogens. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2016.
48 Stokinger HE. A review of world literature finds iron oxides noncarcinogenic. Am Ind Hyg Assoc J. 1984; 45(2):127–133. 10.1080/15298668491399497 6367411
49 Boyd JT, Doll R, Faulds JS, Leiper J. Cancer of the lung in iron ore (haematite) miners. Br J Ind Med. 1970; 27(2):97–105. 10.1136/oem.27.2.97 5448525
50 Hill MA, Watson CR, Moss OR. NEWCAS: An interactive computer program for particle size analysis. Richland, WA: Pacific Northwest Laboratory; 1977. PNL-2405, UC-32.
51 King-Herbert A, Thayer K. NTP workshop: Animal models for the NTP rodent cancer bioassay: Stocks and strains—should we switch? Toxicol Pathol. 2006; 34(6):802–805. 10.1080/01926230600935938 17162538
52 Maronpot RR, Boorman GA. Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982; 10(2):71–78. 10.1177/019262338201000210 28094716
53 Boorman GA, Montgomery CA Jr, Eustis SL, Wolfe MJ, McConnell EE, Hardisty JF. Quality assurance in pathology for rodent carcinogenicity studies. In: Milman HA, Weisburger EK, editors. Handbook of Carcinogen Testing. Park Ridge, NJ: Noyer Publications; 1985. p. 345–357.
54 Gart JJ, Chu KC, Tarone RE. Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979; 62(4):957–974. 285297
55 Dunnett CW. A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955; 50(272):1096–1121. 10.1080/01621459.1955.10501294
56 Williams DA. A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971; 27(1):103-117. 10.2307/2528930 5547548
57 Williams DA. The comparison of several dose levels with a zero dose control. Biometrics. 1972; 28(2):519-531. 10.2307/2556164 5037867
58 Shirley E. A non-parametric equivalent of Williams' test for contrasting increasing dose levels of a treatment. Biometrics. 1977; 33(2):386-389. 10.2307/2529789 884197
59 Williams DA. A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986; 42(1):183-186. 10.2307/2531254 3719054
60 Dunn OJ. Multiple comparisons using rank sums. Technometrics. 1964; 6(3):241–252. 10.1080/00401706.1964.10490181
61 Jonckheere AR. A distribution-free k-sample test against ordered alternatives. Biometrika. 1954; 41(1/2):133–145. 10.2307/2333011
62 Dixon WJ, Massey FJ Jr. Introduction to statistical analysis. 2nd ed. New York, NY: McGraw-Hill Book Company, Inc; 1957. p. 276–278, 412.
63 Bartlett MS. Sub-sampling for attributes. J R Stat Soc. 1937; 4(1):131–135.
64 Kruskal WH, Wallis WA. Use of ranks in one-criterion variance analysis. J Am Stat Assoc. 1952; 47(260):583–621. 10.1080/01621459.1952.10483441
65 Wilson KV. A distribution-free test of analysis of variance hypotheses. Psychol Bull. 1956; 53(1):96. 10.1037/h0047975 13289969
66 Wilcoxon F. Individual comparisons by ranking methods. Biometrics Bull. 1945; 1(6):80-83. 10.2307/3001968
67 Bhattacharyya GK, Johnson RA. Fisher-Irwin exact test. In: Bhattacharyya GK, Johnson RA, editors. Statistical Concepts and Methods. New York, NY: John Wiley and Sons; 1977.
68 Code of Federal Regulations (CFR). 21:Part 58.
69 National Toxicology Program (NTP). TOX-91: Pathology tables, survival and growth curves from NTP short-term studies. Research Triangle Park, NC; 2020. 10.22427/NTP-DATA-TOX-91
70 Cesta M, Dixon D, Staska L, Herbert R. National Toxicology Program nonneoplastic lesion atlas: Lung. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2014. [Accessed: October 9, 2019]. https://ntp.niehs.nih.gov/nnl/respiratory/lung/index.htm
71 Cesta M, Miller R. National Toxicology Program nonneoplastic lesion atlas: Nose. Research Triangle Park, NC: U.S. Department of Health and Human Services, Public Health Service, National Toxicology Program; 2014. [Accessed: October 9, 2019]. https://ntp.niehs.nih.gov/nnl/respiratory/nose/index.htm
72 Morrow PE. Possible mechanisms to explain dust overloading of the lungs. Fundam Appl Toxicol. 1988; 10(3):369–384. 10.1093/toxsci/10.3.369 3286345
73 Conti P, DiGioacchino M. MCP-1 and RANTES are mediators of acute and chronic inflammation. Allergy Asthma Proc. 2001; 22(3):133-137. 10.2500/108854101778148737 11424873
74 Wisniowski PE, Spech RW, Wu MIN, Doyle NA, Pasula R, Martin WJ. Vitronectin protects alveolar macrophages from silica toxicity. Am J Respir Crit Care Med. 2000; 162(2):733–739. 10.1164/ajrccm.162.2.9808015 10934113
75 Bomhard EM. Particle-induced pulmonary alveolar proteinosis and subsequent inflammation and fibrosis: A toxicologic and pathologic review. Toxicol Pathol. 2017; 45(3):389–401. 10.1177/0192623316688959 28136187
76 Woolhiser M, McCay JA. Delayed assessment of immunological function allowing for transportation of lymphoid tissues to distant laboratory sites. Toxicol Methods. 1999; 9(3):165–171. 10.1080/105172399242672
77 White KL Jr, Germolec DR, Booker CD, Hernendez DM, McCay JA, Delclos KB, Newbold RR, Weis C, Guo TL. Dietary methoxychlor exposure modulates splenic natural killer cell activity, antibody-forming cell response and phenotypic marker expression in F0 and F1 generations of Sprague Dawley rats. Toxicology. 2005; 207(2):271–281. 10.1016/j.tox.2004.09.011 15596257
78 White KL, Musgrove DL, Brown RD. The sheep erythrocyte T-dependent antibody response (TDAR). In: Dietert RR, editor. Immunotoxicity Testing: Methods and Protocols. New York, NY: Humana Press; 2010. p. 173–184.
79 Temple L, Kawabata TT, Munson AE, White KL Jr. Comparison of ELISA and plaque-forming cell assays for measuring the humoral immune response to SRBC in rats and mice treated with benzo[a]pyrene or cyclophosphamide. Fundam Appl Toxicol. 1993; 21(4):412–419. 10.1006/faat.1993.1116 8253294