# Results

## Data Availability

The National Toxicology Program (NTP) evaluated all study data. Data relevant for evaluating toxicological findings are presented here. All study data are available in the NTP Chemical Effects in Biological Systems (CEBS) database: https://doi.org/10.22427/NTP-DATA-TOX-91.^69^

## Two-week Studies of Abrasive Blasting Agents in Male F344/NTac Rats

### Blasting Sand

All core study rats survived to the end of the study; no significant differences were observed in mean body weights or body weight gains between exposed groups and the chamber control group (Table 3). No clinical observations were related to blasting sand exposure.

Table 3 Survival and Body Weights of Male F344/NTac Rats in the Two-week Inhalation Studies of Abrasive Blasting Agents^a^

Concentration (mg/m^3^) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Control Groups (%)
Blasting Sand
0 | 5/5 | 100 ± 3 | 159 ± 3 | 59 ± 2
3 | 5/5 | 100 ± 3 | 151 ± 5 | 51 ± 3 | 95
15 | 5/5 | 100 ± 3 | 154 ± 4 | 53 ± 2 | 97
30 | 5/5 | 100 ± 3 | 156 ± 2 | 55 ± 2 | 98
Coal Slag
0 | 5/5 | 85 ± 2 | 141 ± 2 | 56 ± 3
3 | 5/5 | 86 ± 3 | 145 ± 5 | 59 ± 4 | 103
15 | 5/5 | 85 ± 3 | 143 ± 3 | 58 ± 1 | 102
30 | 5/5 | 87 ± 3 | 142 ± 3 | 55 ± 4 | 100
Crushed Glass
0 | 5/5 | 87 ± 4 | 146 ± 5 | 59 ± 3
3 | 5/5 | 86 ± 4 | 144 ± 4 | 58 ± 4 | 99
15 | 5/5 | 87 ± 4 | 148 ± 5 | 61 ± 3 | 101
30 | 5/5 | 86 ± 4 | 148 ± 3 | 62 ± 2 | 101
Garnet
0 | 5/5 | 91 ± 1 | 146 ± 3 | 55 ± 3
3 | 5/5 | 91 ± 1 | 154 ± 4 | 63 ± 3 | 105
15 | 5/5 | 92 ± 1 | 157 ± 4 | 64 ± 4 | 107
30 | 5/5 | 91 ± 0 | 150 ± 4 | 59 ± 4 | 103
Specular Hematite
0 | 5/5 | 94 ± 3 | 146 ± 5 | 52 ± 4
3 | 5/5 | 92 ± 3 | 147 ± 3 | 55 ± 2 | 101
15 | 5/5 | 91 ± 2 | 148 ± 5 | 58 ± 3 | 102
30 | 5/5 | 91 ± 4 | 143 ± 5 | 53 ± 2 | 98
60 | 5/5 | 91 ± 2 | 143 ± 4 | 51 ± 5 | 98

^a^ Weights and weight changes are given as mean ± standard error. Differences from the chamber control group are not significant by the Dunnett test.

^b^ Number of animals surviving at 16 days/number initially in group.

Absolute and relative lung, bronchial lymph node, and mediastinal lymph node weights of core study and tissue burden rats exposed to blasting sand were similar to those of the chamber control group (Table 4). For all five of the 2-week studies, only the day 16 body weight data for the core and tissue burden rats are shown in Table 4.

Table 4 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Male F344/NTac Rats in the Two-week Inhalation Studies of Abrasive Blasting Agents^a^

| Chamber Control | 3 mg/m^3^ | 15 mg/m^3^ | 30 mg/m^3^ | 60 mg/m^3^
n | 5 | 5 | 5 | 5 | 5
Blasting Sand Core Study Rats
Necropsy Body Wt. | 159 ± 3 | 151 ± 5 | 154 ± 4 | 156 ± 2 | –
Lung
Absolute | 1.13 ± 0.03 | 1.09 ± 0.08 | 1.25 ± 0.07 | 1.27 ± 0.10 | –
Relative | 7.10 ± 0.16 | 7.15 ± 0.28 | 8.19 ± 0.61 | 8.18 ± 0.59 | –
Blasting Sand Tissue Burden Rats^b^
Day 16 Body Wt. | 146 ± 4 | 153 ± 5 | 158 ± 3 | 160 ± 4* | –
Lung
Absolute | 0.94 ± 0.05 | 0.89 ± 0.07 | 0.93 ± 0.06 | 0.86 ± 0.05^c^ | –
Relative | 6.44 ± 0.17 | 5.82 ± 0.33 | 5.86 ± 0.43 | 5.37 ± 0.43^c^ | –
Bronchial Lymph Node
Absolute | 0.016 ± 0.004 | 0.017 ± 0.004 | 0.017 ± 0.003 | 0.016 ± 0.004 | –
Relative | 0.11 ± 0.03 | 0.11 ± 0.03 | 0.11 ± 0.02 | 0.10 ± 0.02 | –
Mediastinal Lymph Node
Absolute | 0.045 ± 0.008 | 0.035 ± 0.003 | 0.038 ± 0.003 | 0.041 ± 0.005 | –
Relative | 0.31 ± 0.05 | 0.23 ± 0.02 | 0.24 ± 0.02 | 0.26 ± 0.03 | –
Coal Slag Core Study Rats
Necropsy Body Wt. | 141 ± 2 | 145 ± 5 | 143 ± 3 | 142 ± 3 | –
Lung
Absolute | 1.11 ± 0.06 | 1.36 ± 0.19 | 1.41 ± 0.18 | 1.17 ± 0.05 | –
Relative | 7.87 ± 0.34 | 9.29 ± 1.24 | 9.84 ± 1.27 | 8.25 ± 0.25 | –
Coal Slag Tissue Burden Rats
Day 16 Body Wt. | 137 ± 3 | 141 ± 4 | 135 ± 2 | 139 ± 6 | –
Lung
Absolute | 0.73 ± 0.02 | 0.73 ± 0.04 | 0.79 ± 0.03 | 0.88 ± 0.06* | –
Relative | 5.34 ± 0.08 | 5.19 ± 0.18 | 5.87 ± 0.28 | 6.37 ± 0.48* | –
Bronchial Lymph Node
Absolute | 0.010 ± 0.001 | 0.011 ± 0.001 | 0.009 ± 0.002 | 0.016 ± 0.005 | –
Relative | 0.07 ± 0.01 | 0.08 ± 0.01 | 0.07 ± 0.01 | 0.11 ± 0.04 | –
Mediastinal Lymph Node
Absolute | 0.042 ± 0.004 | 0.035 ± 0.003 | 0.033 ± 0.003 | 0.039 ± 0.003 | –
Relative | 0.30 ± 0.03 | 0.25 ± 0.03 | 0.25 ± 0.02 | 0.28 ± 0.01 | –
Crushed Glass Core Study Rats
Necropsy Body Wt. | 146 ± 5 | 144 ± 4 | 148 ± 5 | 148 ± 3 | –
Lung
Absolute | 1.07 ± 0.05 | 1.10 ± 0.03 | 1.27 ± 0.07* | 1.22 ± 0.05* | –
Relative | 7.33 ± 0.31 | 7.63 ± 0.30 | 8.67 ± 0.57 | 8.31 ± 0.44 | –
Crushed Glass Tissue Burden Rats
Day 16 Body Wt. | 140 ± 4 | 140 ± 4 | 144 ± 2 | 146 ± 6 | –
Lung
Absolute | 0.88 ± 0.04 | 0.92 ± 0.08 | 0.82 ± 0.02 | 0.86 ± 0.04 | –
Relative | 6.37 ± 0.46 | 6.52 ± 0.43 | 5.68 ± 0.10 | 5.92 ± 0.36 | –
Bronchial Lymph Node
Absolute | 0.018 ± 0.002 | 0.013 ± 0.002 | 0.013 ± 0.001 | 0.016 ± 0.002 | –
Relative | 0.13 ± 0.02 | 0.10 ± 0.02 | 0.09 ± 0.01 | 0.11 ± 0.02 | –
Mediastinal Lymph Node
Absolute | 0.030 ± 0.004 | 0.028 ± 0.001 | 0.032 ± 0.004 | 0.032 ± 0.005 | –
Relative | 0.21 ± 0.03 | 0.20 ± 0.01 | 0.22 ± 0.03 | 0.22 ± 0.03 | –
Garnet Core Study Rats
Necropsy Body Wt. | 146 ± 3 | 154 ± 4 | 157 ± 4 | 150 ± 4 | –
Lung
Absolute | 1.14 ± 0.07 | 1.12 ± 0.07 | 1.28 ± 0.05 | 1.29 ± 0.09 | –
Relative | 7.84 ± 0.62 | 7.30 ± 0.49 | 8.18 ± 0.31 | 8.62 ± 0.52 | –
Garnet Tissue Burden Rats
Day 16 Body Wt. | 145 ± 6 | 155 ± 3 | 156 ± 4 | 145 ± 4 | –
Lung
Absolute | 0.82 ± 0.05 | 0.81 ± 0.04 | 0.83 ± 0.02 | 0.84 ± 0.02 | –
Relative | 5.63 ± 0.15 | 5.26 ± 0.31 | 5.33 ± 0.18 | 5.77 ± 0.16 | –
Bronchial Lymph Node
Absolute | 0.012 ± 0.001 | 0.017 ± 0.004 | 0.021 ± 0.003 | 0.013 ± 0.002 | –
Relative | 0.09 ± 0.01 | 0.11 ± 0.03 | 0.14 ± 0.02 | 0.09 ± 0.01 | –
Mediastinal Lymph Node
Absolute | 0.052 ± 0.006 | 0.054 ± 0.006 | 0.051 ± 0.007 | 0.041 ± 0.003 | –
Relative | 0.36 ± 0.05 | 0.35 ± 0.04 | 0.32 ± 0.04 | 0.29 ± 0.02 | –
Specular Hematite Core Study Rats
Necropsy Body Wt. | 146 ± 5 | 147 ± 3 | 148 ± 5 | 143 ± 5 | 143 ± 4
Lung
Absolute | 1.19 ± 0.13 | 1.12 ± 0.06 | 1.18 ± 0.07 | 1.15 ± 0.07 | 1.38 ± 0.17
Relative | 8.13 ± 0.73 | 7.65 ± 0.29 | 7.98 ± 0.31 | 8.08 ± 0.54 | 9.61 ± 1.06
Specular Hematite Tissue Burden Rats
Day 16 Body Wt. | 138 ± 5 | 138 ± 5 | 143 ± 2 | 134 ± 4 | 139 ± 3
Lung
Absolute | 0.81 ± 0.04 | 0.78 ± 0.02 | 0.87 ± 0.04 | 0.83 ± 0.11 | 0.79 ± 0.04
Relative | 5.89 ± 0.10 | 5.67 ± 0.21 | 6.07 ± 0.19 | 6.21 ± 0.73 | 5.68 ± 0.25
Bronchial Lymph Node
Absolute | 0.018 ± 0.003 | 0.017 ± 0.002 | 0.015 ± 0.002 | 0.013 ± 0.001 | 0.012 ± 0.003
Relative | 0.13 ± 0.02 | 0.12 ± 0.01 | 0.10 ± 0.01 | 0.10 ± 0.01 | 0.09 ± 0.02
Mediastinal Lymph Node
Absolute | 0.029 ± 0.003 | 0.031 ± 0.002 | 0.033 ± 0.004 | 0.034 ± 0.005 | 0.030 ± 0.003
Relative | 0.21 ± 0.02 | 0.23 ± 0.02 | 0.23 ± 0.03 | 0.26 ± 0.04 | 0.21 ± 0.02

* Significantly different (p ≤ 0.05) from the chamber control group by the Williams or Dunnett tests.

^a^ Organ weights (absolute weights) and body weights are given in grams and were recorded on day 16 after exposure for 5 days per week for 2 weeks plus 2 days (12 exposures); organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error). There was no 60 mg/m3 group for blasting sand, coal slag, crushed glass, or garnet.

^b^ Lung and lymph node tissue burden data are in Appendix B.

^c^ n = 4.

Blasting sand lung burdens continued to increase through the last exposure day (day 16) indicating that steady-state lung burdens were not achieved during the study (Table B-1). The calculated clearance rate of blasting sand was slower and the clearance half-life longer in the 3 mg/m^3^ group compared to the 15 and 30 mg/m^3^ groups (Table B-3). Clearance half-life values were 93, 35, and 33 days for the 3, 15, and 30 mg/m^3^ groups, respectively (Table B-3). Blasting sand lung burdens in the total lung decreased approximately 15% in the 3 mg/m^3^ group and approximately 34% to 36% in the 15 and 30 mg/m^3^ groups during recovery (Table B-1). Blasting sand lung burdens at the end of the exposure interval (day 16) were approximately 124, 581, and 1,337 μg blasting sand/g lung for rats exposed to 3, 15, and 30 mg/m^3^, respectively (Table B-1). Steady-state lung burdens for blasting sand were 975, 1,993, and 3,931 μg blasting sand/total lung in the 3, 15, and 30 mg/m^3^ groups, respectively (Table B-3). Blasting sand burdens for the mediastinal and bronchial lymph nodes were indistinguishable from solvent blanks (Table B-3).

Minimal histiocytic cellular infiltration^70,71^ occurred in the alveolus of the lung of exposed groups of rats, and the incidence in the 30 mg/m^3^ group was significantly greater than that in the chamber control group (Table 5). This lesion was characterized by an increase in the number of alveolar macrophages diffusely scattered throughout the lungs. The test article was visible under polarized light in the cytoplasm of some of the macrophages.

Table 5 Incidences of Selected Nonneoplastic Lesions in Male F344/NTac Rats in the Two-week Inhalation Studies of Abrasive Blasting Agents

| Chamber Control | 3 mg/m^3^ | 15 mg/m^3^ | 30 mg/m^3^ | 60 mg/m^3^
Blasting Sand
Lung^a^ | 5 | 5 | 5 | 5 | –
Alveolus, infiltration cellular, histiocyte^b^ | 1 (1.0)^c^ | 4 (1.0) | 4 (1.0) | 5** (1.0) | –
Coal Slag
Lung | 5 | 5 | 5 | 5 | –
Infiltration cellular, histiocyte diffuse | 0 | 0 | 5** (1.0) | 5** (1.0) | –
Inflammation, focal | 0 | 0 | 1 (1.0) | 2 (1.0) | –
Proteinosis | 0 | 1 (1.0) | 2 (1.0) | 0 | –
Crushed Glass
Nose | 5 | 5 | 5 | 5 | –
Hypertrophy, goblet cell | 1 (1.0) | 4 (1.3) | 5** (1.6) | 5** (2.0) | –
Larynx | 5 | 5 | 5 | 5 | –
Epiglottis, epithelial hyperplasia | 0 | 1 (1.0) | 5** (1.6) | 5** (1.2) | –
Epiglottis, metaplasia, squamous | 0 | 0 | 5** (1.0) | 5** (1.0) | –
Epiglottis, inflammation | 0 | 1 (1.0) | 5** (1.0) | 5** (1.0) | –
Garnet
Lung | 5 | 5 | 5 | 5 | –
Inflammation, chronic active | 0 | 2 (2.0) | 5** (1.2) | 5** (2.4) | –
Pigmentation | 0 | 5** (1.0) | 5** (2.0) | 5** (2.0) | –
Specular Hematite
Nose | 5 | 5 | 5 | 5 | 5
Goblet cell, nasopharyngeal duct, hypertrophy | 0 | 0 | 0 | 1 (1.0) | 5** (1.0)
Lung | 5 | 5 | 5 | 5 | 5
Foreign body material | 0 | 5** (1.0) | 5** (2.0) | 5** (2.2) | 5** (3.0)
Alveolus, infiltration cellular, histiocyte | 0 | 0 | 2 (1.0) | 5** (1.2) | 5** (2.0)

** Significantly different (p ≤ 0.01) from the chamber control group by the Fisher exact test.

^a^ Number of animals with tissue examined microscopically; there was no 60 mg/m3 group for blasting sand, coal slag, crushed glass, or garnet.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

### Coal Slag

All core study rats survived to the end of the study; no significant differences were observed in mean body weights or body weight gains between exposed groups and the chamber control group (Table 3). One rat in the 30 mg/m^3^ group had an ocular discharge on days 5 and 8; no other clinical observations associated with coal slag exposure were noted.

Sporadic increases (some statistically significant) were observed in the absolute and relative lung and bronchial and mediastinal lymph node weights in animals exposed to coal slag; however, there was no consistent pattern of increasing organ weights over time in the lung burden animals (Table 4). Furthermore, the lung weights from the core study animals were inconsistent with the lung weights from tissue burden animals. Consequently, the organ weight data were determined not to be toxicologically significant.

Coal slag lung burdens continued to increase through the last exposure day (day 16) indicating that steady-state lung burdens were not achieved during the study (Table B-4). The calculated clearance rate of coal slag was faster and the clearance half-life shorter in the 3 mg/m^3^ group compared to the 15 and 30 mg/m^3^ groups (Table B-6).

During the 21-day recovery period, coal slag lung burdens decreased approximately 28%, 23%, and 19% in the 3, 15, and 30 mg/m^3^ groups, respectively (Table B-4). Coal slag lung burdens at the end of the exposure interval (day 16) were approximately 162, 673, 1,104 μg coal slag/g lung for rats exposed to 3, 15, and 30 mg/m^3^ of coal slag, respectively (Table B-4). Steady-state lung burdens for coal slag were 524, 2,986, and 6,419 μg coal slag/total lung in the 3, 15, and 30 mg/m^3^ groups, respectively (Table B-6). Coal slag tissue burdens for the mediastinal and bronchial lymph nodes were indistinguishable from solvent blanks (Table B-6).

No gross lesions were associated with coal slag exposure. Microscopic lesions were limited to the lung (Table 5). Histiocytic cellular infiltration occurred in all animals in the 15 and 30 mg/m^3^ groups and was graded minimal in all cases; the lesion did not occur in any chamber control animals or those exposed to 3 mg/m^3^. Two rats from the 30 mg/m^3^ group and one rat from the 15 mg/m^3^ group had minimal, focal, chronic active inflammation. Two rats from the 15 mg/m^3^ group and one rat from the 3 mg/m^3^ group had minimal alveolar proteinosis.

Histiocytic cellular infiltration was characterized by increased numbers of alveolar macrophages within the alveoli. The chronic active inflammation was characterized as small, focal accumulations of macrophages and neutrophils with scant cellular debris within the alveolar spaces and interstitium. The alveolar proteinosis was characterized by small amounts of eosinophilic, proteinaceous material within some alveolar spaces.

### Crushed Glass

All core study rats survived to the end of the study; no significant differences were observed in mean body weights or body weight gains between exposed groups and the chamber control group (Table 3). No clinical observations were associated with exposure to crushed glass.

The absolute lung weights of core study rats exposed to 15 or 30 mg/m^3^ were significantly increased approximately 19% and 14%, respectively, compared to that of the chamber control group (Table 4). Relative lung weights from these groups were approximately 18% and 13% greater than the chamber control group, respectively. The absolute and relative lung weights of tissue burden rats exposed to crushed glass were similar to those of the chamber control group.

Crushed glass lung burdens continued to increase through the last exposure day (day 16), indicating that steady-state lung burdens were not achieved during the study (Table B-7). The calculated clearance rate of crushed glass was faster and the clearance half-life shorter in the 3 mg/m^3^ group compared to the 15 and 30 mg/m^3^ groups (Table B-9). Clearance half-life values were 10, 17, and 16 days for the 3, 15, and 30 mg/m^3^ groups, respectively (Table B-9). Burdens of crushed glass in the total lung were generally proportional to exposure concentration except when comparing the 3 mg/m^3^ group to the 15 and 30 mg/m^3^ groups at days 5 and 37 (Table B-7). During the 21-day recovery period, total lung crushed glass burdens, as measured in day 37 samples, decreased to approximately 22%, 42%, and 41% of the day 16 burdens in the 3, 15, and 30 mg/m^3^ groups, respectively (Table B-7). Crushed glass lung burdens at the end of the exposure interval (day 16) were approximately 61, 347, and 604 μg crushed glass/g lung for rats exposed to 3, 15, or 30 mg/m^3^, respectively (Table B-7). Steady-state lung burdens for crushed glass were 80, 586, and 1,035 μg crushed glass/total lung in the 3, 15, and 30 mg/m^3^ groups, respectively (Table B-9). These values were the lowest for all abrasive blasting agents tested. Comparable values for garnet were 474, 5,089, and 9,089 μg garnet/total lung for rats exposed to 3, 15, or 30 mg/m^3^, respectively (Table B-12). Crushed glass burdens for the mediastinal and bronchial lymph nodes were indistinguishable from solvent blanks (Table B-8).

No gross lesions were associated with crushed glass exposure. Microscopic lesions occurred in the nose and larynx (Table 5), but no microscopic lesions were seen in the lungs. All exposed rats, except for one in the 3 mg/m^3^ group, had minimal to mild goblet cell hypertrophy of the respiratory epithelium in the nose. One chamber control rat also had minimal respiratory epithelium goblet cell hypertrophy. The severity of the lesion increased with increasing exposure concentration. In the larynx, all animals in the 15 and 30 mg/m^3^ groups had respiratory epithelial hyperplasia and squamous metaplasia and chronic inflammation. The squamous metaplasia and inflammation were minimal in all cases, but a few cases of respiratory epithelial hyperplasia were considered mild. Additionally, in the 3 mg/m^3^ group, one rat had minimal respiratory epithelial hyperplasia, and one rat had minimal inflammation.

Goblet cell hypertrophy of the respiratory epithelium of the nose was characterized by goblet cells that were taller than those in the chamber control animals and contained increased amounts of mucin. The laryngeal lesions were seen mainly at the base of the epiglottis. Epithelial hyperplasia of the laryngeal epithelium was characterized by an increase in the number of epithelial cell layers (two to five layers as opposed to one to three layers in the chamber control groups). Squamous metaplasia was diagnosed when the normally cuboidal epithelial cells were flattened and elongated. Chronic inflammation was characterized most frequently by increased numbers of mononuclear cells in the lamina propria. In some rats in the 15 and 30 mg/m^3^ groups, superficial, focal, nodular expansions of the lamina propria contained mononuclear cells, fewer neutrophils, and prominent capillaries. These nodular expansions bulged into the laryngeal lumen and were covered by hyperplastic and squamous metaplastic epithelium.

### Garnet

All core study rats survived to the end of the study; no significant differences were observed in mean body weights or body weight gains between exposed groups and the chamber control group (Table 3). No clinical observations were associated with garnet exposure.

Sporadic increases (some statistically significant) were observed in the absolute and relative lung and bronchial and mediastinal lymph node weights in animals exposed to garnet (Table 4); however, there was no consistent pattern of increasing organ weights over time in the lung burden animals. Furthermore, the lung weights from the core study animals were inconsistent with the lung weights from tissue burden animals. Consequently, the organ weight data were determined not to be toxicologically significant.

Garnet lung burdens continued to increase through the last exposure day (day 16), indicating that steady-state lung burdens were not achieved during this study (Table B-10). The calculated clearance rate of garnet was faster and the clearance half-life shorter in the 3 mg/m^3^ group compared to the 15 and 30 mg/m^3^ groups (Table B-12). Garnet lung burdens in the total lung decreased approximately 34%, 15%, and 15% in the 3, 15, and 30 mg/m^3^ groups, respectively, between the last day of exposure (day 16) and the last day of recovery (day 37) (Table B-10). Garnet lung burdens at the end of the exposure interval (day 16) were approximately 160, 714, and 1,280 μg garnet/g lung for rats exposed to 3, 15, or 30 mg/m^3^, respectively (Table B-10). Garnet burdens for the mediastinal and bronchial lymph nodes were indistinguishable from solvent blanks (Table B-11).

No gross lesions were associated with garnet exposure. Microscopic lesions were observed in the lung only (Table 5). A treatment-related increase in the incidence of chronic active inflammation was observed, as the lesion occurred in two 3 mg/m^3^ rats and all 15 and 30 mg/m^3^ rats. The severity ranged from minimal to mild in the 3 and 15 mg/m^3^ groups and was mild to moderate in the 30 mg/m^3^ group. Minimal to mild pigmentation occurred in all exposed animals and was generally more severe in the 15 and 30 mg/m^3^ groups than in the 3 mg/m^3^ group.

Chronic active inflammation of the lung was characterized by a diffuse increase in alveolar macrophages with occasional neutrophils within alveolar spaces. Scattered foci of more intense inflammation with accumulations of lymphocytes, macrophages, neutrophils, fibrin, and cellular debris obscured the alveolar architecture. Numerous lymphocytes were also observed surrounding pulmonary vessels. Pigmentation was characterized by brown to black foreign bodies (granular material) within the cytoplasm of alveolar macrophages. The pigmented material is likely the test agent because this material was not seen in chamber control animals, it was present within macrophages, and it was more severe in animals exposed to higher concentrations of garnet.

### Specular Hematite

All core study rats survived to the end of the study, and final mean body weights and body weight gains of all exposed groups were similar to those of the chamber control group (Table 3). No clinical observations were related to specular hematite exposure.

Differences between the exposed and chamber control core study groups in absolute and relative lung weights were not significant (Table 4). Sporadic increases (some statistically significant) were observed in the absolute and relative lung and bronchial and mediastinal lymph node weights in animals exposed to specular hematite. No consistent pattern was observed, however, of increasing organ weights over time in the lung burden animals (in fact, there were some statistically significant decreases in lung weight). Furthermore, the lung weights from the core study animals were inconsistent with the lung weights from tissue burden animals. Consequently, the organ weight data were determined not to be toxicologically significant.

Specular hematite lung burdens continued to increase through the last exposure day (day 16), indicating that steady-state lung burdens were not achieved during this study (Table B-13). The calculated clearance half-lives were 48, 30, 50, and 44 days for the 3, 15, 30, and 60 mg/m^3^ groups, respectively (Table B-15). During the 21-day recovery period, 26%, 38%, 25%, and 28% of the specular hematite deposited in the lungs was eliminated in the 3, 15, 30, and 60 mg/m^3^ groups, respectively (Table B-13). Specular hematite lung burdens at the end of the exposure interval (day 16) were approximately 149, 662, 1,126, and 2,282 μg specular hematite/g lung for rats exposed to 3, 15, 30, or 60 mg/m^3^, respectively (Table B-13). Steady-state lung burdens for specular hematite were 559, 1,868, 4,557, and 8,057 μg specular hematite/total lung in the 3, 15, 30, and 60 mg/m^3^ groups, respectively (Table B-15). Specular hematite burdens for the mediastinal and bronchial lymph nodes were indistinguishable from solvent blanks (Table B-14).

At necropsy, the lungs of all rats exposed to 60 mg/m^3^ and most rats exposed to 30 mg/m^3^ were tan in color. In the lung, the presence of foreign body material in all exposed groups and histiocytic cellular infiltration in the 30 and 60 mg/m^3^ groups were significantly greater than those in the chamber control group (Table 5). The severity of foreign body accumulation increased with increasing exposure concentration. This material was determined to be the test article because foreign body material was not seen in chamber control animals, it was present within macrophages, and it was more severe in animals exposed to higher concentrations of specular hematite. The incidence of goblet cell hypertrophy in the nasopharyngeal duct of the nose was significantly increased in 60 mg/m^3^ rats. The histiocytic cellular infiltration was characterized by an increase in the number of alveolar macrophages (histiocytes) within the lung. Many of these macrophages were enlarged and contained brown to golden-brown, refractile, granular material, determined to be foreign bodies, within the cytoplasm. Some of this material was also free in the alveoli. Goblet cell hypertrophy in the nasopharyngeal duct was characterized by an increase in the height of affected goblet cells, which were distended with mucus.

Rationale for Selection of Test Articles, Exposure Concentrations, and Exposure Duration for the 39-week Studies: Specular hematite and crushed glass appeared to be the least toxic of the four alternatives to blasting sand tested in the 2-week studies because of the absence of induced lung inflammation (observed for coal slag and garnet) and proteinosis (observed for coal slag), but crushed glass had relatively faster clearance rates (shorter clearance half-lives) compared to the other test articles. Crushed glass also appeared to be more reactive to the upper respiratory tract (larynx) than the other blasting agents. Therefore, specular hematite (instead of crushed glass) was selected as the alternative blasting agent to compare to blasting sand in separate 39-week studies in Sprague Dawley rats. Informed by the low lung toxicity and burdens in F344/NTac rats at the exposure concentrations tested in the 2-week inhalation studies, exposure concentrations of 0, 15, 30, and 60 mg/m^3^ were selected (3 mg/m^3^ was removed) for the 39-week studies. The 39-week time point was selected to allow adequate time for the development of an adverse histopathological response (including interstitial fibrosis) in the lung. Comparisons between the two agents could then be made after evaluating both the time for the development of fibrosis and the severity of fibrosis over time.

## Thirty-nine-week Studies of Abrasive Blasting Agents in Sprague Dawley Rats

### Blasting Sand

All male core study rats survived to the end of the study; mean body weights and body weight gains of all exposed groups were similar to those of the chamber control group throughout the study (Table 6 and Figure 1). No clinical observations were associated with exposure to blasting sand.

Table 6 Mean Body Weights and Survival of Male Sprague Dawley Rats in the 39-week Inhalation Study of Blasting Sand

Day | 0 mg/m^3^ | | 15 mg/m^3^ | | | 30 mg/m^3^ | | | 60 mg/m^3^
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 142 | 62 | 141 | 99 | 62 | 141 | 99 | 62 | 141 | 99 | 62
8^a^ | 192 | 57 | 191 | 100 | 57 | 190 | 99 | 57 | 191 | 100 | 57
15 | 237 | 57 | 236 | 100 | 57 | 235 | 99 | 57 | 239 | 101 | 57
22 | 274 | 57 | 273 | 100 | 57 | 272 | 99 | 57 | 277 | 101 | 57
29^a^ | 299 | 44 | 301 | 101 | 44 | 298 | 100 | 44 | 305 | 102 | 44
36 | 320 | 44 | 323 | 101 | 44 | 319 | 100 | 44 | 329 | 103 | 44
43 | 338 | 44 | 341 | 101 | 44 | 338 | 100 | 44 | 348 | 103 | 44
50 | 354 | 44 | 356 | 101 | 44 | 353 | 100 | 44 | 363 | 103 | 44
57^a^ | 365 | 39 | 369 | 101 | 39 | 368 | 101 | 39 | 377 | 103 | 39
64 | 376 | 39 | 382 | 101 | 39 | 381 | 101 | 39 | 389 | 103 | 39
71 | 386 | 39 | 392 | 102 | 39 | 391 | 101 | 39 | 398 | 103 | 39
78 | 397 | 39 | 403 | 102 | 39 | 401 | 101 | 39 | 409 | 103 | 39
85 | 404 | 39 | 411 | 102 | 39 | 410 | 101 | 39 | 416 | 103 | 39
92 | 412 | 39 | 419 | 102 | 39 | 417 | 101 | 39 | 423 | 103 | 39
99 | 418 | 39 | 426 | 102 | 39 | 424 | 102 | 39 | 430 | 103 | 39
106 | 423 | 39 | 432 | 102 | 39 | 431 | 102 | 39 | 438 | 103 | 39
134^a^ | 444 | 26 | 444 | 100 | 26 | 449 | 101 | 26 | 453 | 102 | 26
162 | 461 | 26 | 460 | 100 | 26 | 466 | 101 | 26 | 470 | 102 | 26
190^a^ | 477 | 13 | 470 | 99 | 13 | 485 | 102 | 13 | 485 | 102 | 13
218 | 489 | 13 | 487 | 100 | 13 | 499 | 102 | 13 | 498 | 102 | 13
246 | 497 | 13 | 500 | 101 | 13 | 512 | 103 | 13 | 510 | 103 | 13

^a^ Interim evaluations occurred during weeks 1, 4, 8, 16, and 26.

Figure 1

Growth Curves for Male Sprague Dawley Rats Exposed to Blasting Sand by Inhalation for 39 Weeks

Lungs and bronchial and mediastinal lymph nodes were weighed in male rats used for tissue burden analyses (Table 7). The absolute and relative lung weights in the 30 and 60 mg/m^3^ groups were significantly increased compared to those in the chamber control group beginning at week 16 or 8, respectively. The absolute and relative bronchial lymph node weights in the 60 mg/m^3^ group at all time points and in the 30 mg/m^3^ group at week 26 were significantly increased compared to those in the chamber control group. The absolute mediastinal lymph node weights were significantly increased at weeks 16, 26, and 39 in the 60 mg/m^3^ group, and the relative mediastinal lymph node weights were increased in this group at weeks 16 and 39.

Table 7 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Male Sprague Dawley Tissue Burden Rats in the 39-week Inhalation Study of Blasting Sand^a^

| Chamber Control | 15 mg/m^3^ | 30 mg/m^3^ | 60 mg/m^3^
Week 1
n | 5 | 5 | 5 | 5
Body Wt. | 156 ± 3 | 167 ± 3 | 161 ± 6 | 161 ± 2
Lung
Absolute | 0.93 ± 0.03 | 0.98 ± 0.03 | 0.99 ± 0.05 | 0.98 ± 0.02
Relative | 5.95 ± 0.08 | 5.90 ± 0.12 | 6.17 ± 0.06 | 6.11 ± 0.09
Bronchial Lymph Node
Absolute | 0.012 ± 0.002 | 0.016 ± 0.005 | 0.016 ± 0.003 | 0.025 ± 0.003*
Relative | 0.08 ± 0.01 | 0.09 ± 0.03 | 0.10 ± 0.02 | 0.16 ± 0.02*
Mediastinal Lymph Node
Absolute | 0.027 ± 0.003 | 0.034 ± 0.005 | 0.032 ± 0.005 | 0.032 ± 0.005
Relative | 0.18 ± 0.02 | 0.20 ± 0.03 | 0.20 ± 0.03 | 0.20 ± 0.03
Week 4
n | 5 | 5 | 5 | 5
Body Wt. | 277 ± 7 | 283 ± 8 | 283 ± 6 | 282 ± 7
Lung
Absolute | 1.18 ± 0.04 | 1.27 ± 0.03 | 1.28 ± 0.04 | 1.30 ± 0.04
Relative | 4.27 ± 0.18 | 4.50 ± 0.18 | 4.55 ± 0.10 | 4.63 ± 0.10
Bronchial Lymph Node
Absolute | 0.020 ± 0.002 | 0.025 ± 0.003 | 0.022 ± 0.001 | 0.037 ± 0.004**
Relative | 0.07 ± 0.01 | 0.09 ± 0.01 | 0.08 ± 0.00 | 0.13 ± 0.01**
Mediastinal Lymph Node
Absolute | 0.024 ± 0.004 | 0.032 ± 0.007 | 0.035 ± 0.005 | 0.033 ± 0.010
Relative | 0.08 ± 0.01 | 0.11 ± 0.03 | 0.12 ± 0.02 | 0.12 ± 0.04
Week 8
n | 5 | 5 | 5 | 5
Body Wt. | 363 ± 8 | 359 ± 13 | 346 ± 9 | 363 ± 10
Lung
Absolute | 1.34 ± 0.04 | 1.39 ± 0.04 | 1.39 ± 0.02 | 1.71 ± 0.05**
Relative | 3.69 ± 0.08 | 3.86 ± 0.05 | 4.02 ± 0.07** | 4.69 ± 0.07**
Bronchial Lymph Node
Absolute | 0.023 ± 0.002 | 0.022 ± 0.004 | 0.026 ± 0.007 | 0.043 ± 0.007*
Relative | 0.06 ± 0.01 | 0.06 ± 0.01 | 0.08 ± 0.02 | 0.12 ± 0.02*
Mediastinal Lymph Node
Absolute | 0.032 ± 0.006 | 0.040 ± 0.007 | 0.043 ± 0.008 | 0.053 ± 0.008
Relative | 0.09 ± 0.02 | 0.11 ± 0.02 | 0.12 ± 0.02 | 0.15 ± 0.02
Week 16
n | 5 | 5 | 5 | 5
Body Wt. | 406 ± 21 | 427 ± 14 | 406 ± 11 | 438 ± 18
Lung
Absolute | 1.40 ± 0.05 | 1.55 ± 0.05 | 1.66 ± 0.05** | 1.97 ± 0.07**
Relative | 3.45 ± 0.09 | 3.63 ± 0.05 | 4.09 ± 0.09** | 4.51 ± 0.11**
Bronchial Lymph Node
Absolute | 0.017 ± 0.002 | 0.029 ± 0.006 | 0.045 ± 0.006 | 0.101 ± 0.018**
Relative | 0.04 ± 0.01 | 0.07 ± 0.01 | 0.11 ± 0.01* | 0.23 ± 0.03**
Mediastinal Lymph Node
Absolute | 0.024 ± 0.004 | 0.031 ± 0.003 | 0.038 ± 0.007 | 0.046 ± 0.006*
Relative | 0.06 ± 0.01 | 0.07 ± 0.01 | 0.010 ± 0.02 | 0.11 ± 0.02*
Week 26
n | 4 | 5 | 5 | 5
Body Wt. | 466 ± 22 | 472 ± 14 | 463 ± 9 | 475 ± 5
Lung
Absolute | 1.48 ± 0.02^b^ | 1.67 ± 0.05 | 1.92 ± 0.04** | 2.43 ± 0.15**
Relative | 3.24 ± 0.15 | 3.54 ± 0.06 | 4.16 ± 0.13** | 5.10 ± 0.28**
Bronchial Lymph Node
Absolute | 0.018 ± 0.002^b^ | 0.039 ± 0.005 | 0.077 ± 0.018** | 0.079 ± 0.008**
Relative | 0.04 ± 0.00 | 0.08 ± 0.01 | 0.16 ± 0.04** | 0.17 ± 0.02**
Mediastinal Lymph Node
Absolute | 0.030 ± 0.005^b^ | 0.052 ± 0.007 | 0.075 ± 0.009 | 0.101 ± 0.037*
Relative | 0.07 ± 0.01 | 0.11 ± 0.01 | 0.16 ± 0.02 | 0.21 ± 0.08
Week 39
n | 5 | 5 | 5 | 5
Body Wt. | 507 ± 22 | 499 ± 17 | 495 ± 13 | 504 ± 4
Lung
Absolute | 1.63 ± 0.02 | 1.70 ± 0.04 | 1.96 ± 0.09* | 2.73 ± 0.16**
Relative | 3.24 ± 0.09 | 3.43 ± 0.14 | 3.96 ± 0.15* | 5.41 ± 0.32**
Bronchial Lymph Node
Absolute | 0.015 ± 0.002 | 0.115 ± 0.013 | 0.089 ± 0.019 | 0.193 ± 0.063**
Relative | 0.03 ± 0.01 | 0.23 ± 0.03 | 0.18 ± 0.04 | 0.38 ± 0.12**
Mediastinal Lymph Node
Absolute | 0.020 ± 0.001 | 0.034 ± 0.013 | 0.062 ± 0.017 | 0.072 ± 0.017*
Relative | 0.04 ± 0.00 | 0.07 ± 0.02 | 0.12 ± 0.03 | 0.14 ± 0.03*

* Significantly different (p ≤ 0.05) from the chamber control group by the Dunnett or Williams tests.

** p ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

^b^ n = 5.

The greatest changes in measured bronchoalveolar lavage (BAL) fluid parameters for blasting sand occurred in pulmonary alveolar macrophages, neutrophils, lymphocytes, and lactate dehydrogenase (LDH) activity (Table 8 and Table A-1). Absolute numbers of macrophages, neutrophils, and lymphocytes and LDH activity were significantly increased in BAL fluid of core male rats, most notably at week 39 at the 60 mg/m^3^ blasting sand exposure concentration compared to the chamber control group. The changes in the exposed male rats generally increased in magnitude with exposure concentration and time, with the 60 mg/m^3^ group often most severely affected. Compared to those of the chamber control groups, total BAL fluid cell counts first increased at week 16 in all exposed groups and reached statistical significance at week 26 in the 60 mg/m^3^ group and at week 39 in the remaining exposed groups. The percentage of pulmonary alveolar macrophages in BAL fluid decreased in groups exposed to 30 or 60 mg/m^3^ starting at week 4 and decreased in all exposed groups starting at week 16. This decrease in the percent pulmonary alveolar macrophages resulted from cells, primarily neutrophils and a small number of lymphocytes, infiltrating the lung. Cytotoxic lung injury resulted from blasting sand exposures, as evident from elevated BAL fluid LDH concentrations as early as week 4 of exposure in the 60 mg/m^3^ group. Beginning at week 16, all exposed groups had increased BAL fluid LDH concentrations. The lung injury was not accompanied by an increase in protein exudation from the lung vasculature, as evident from the lack of increases in BAL fluid albumin. Trends in BAL fluid measurements in the female rats were generally similar to those in males.

Table 8 Bronchoalveolar Lavage Data for Sprague Dawley Rats in the 39-week Inhalation Study of Blasting Sand^a^

| Chamber Control | 15 mg/m^3^ | 30 mg/m^3^ | 60 mg/m^3^
n | 8 | 8 | 8 | 8
Male
Viable Cells (%)
Week 4 | 90.53 ± 1.32 | 90.45 ± 1.89 | 94.75 ± 1.26* | 94.76 ± 0.70*
Week 16 | 70.20 ± 4.96 | 79.11 ± 4.31 | 77.96 ± 3.26 | 84.70 ± 2.26
Week 26 | 77.31 ± 2.77 | 87.55 ± 1.97* | 87.26 ± 2.08 | 87.00 ± 1.91
Week 39 | 93.44 ± 2.17 | 92.21 ± 2.94 | 95.85 ± 1.06 | 98.19 ± 0.27
Total Cells Counted
Week 4 | 248.8 ± 24.4 | 249.4 ± 23.2 | 280.6 ± 32.6 | 301.3 ± 30.6
Week 16 | 308 ± 67.0 | 413 ± 8.0 | 439 ± 73.0 | 502 ± 86.0
Week 26 | 186.3 ± 22.4 | 184.4 ± 28.7 | 262.5 ± 32.0 | 466.9 ± 52.4**
Week 39 | 128 ± 17.0 | 339 ± 65.0** | 450 ± 64.0** | 1,849 ± 301**
Macrophages (%)
Week 4 | 99.6 ± 0.2 | 99.6 ± 0.2 | 92.8 ± 2.1** | 61.9 ± 3.4**
Week 16 | 99.9 ± 0.1 | 75.5 ± 3.4** | 49.7 ± 2.9** | 51.2 ± 4.6**
Week 26 | 99.8 ± 0.1 | 69.9 ± 3.2** | 48.7 ± 4.9** | 33.3 ± 3.5**
Week 39 | 99.6 ± 0.2 | 57.0 ± 4.3** | 53.4 ± 4.8** | 43.6 ± 5.0**
Absolute Macrophages (#/µL)
Week 4 | 247.8 ± 24.5 | 248.5 ± 23.2 | 260.1 ± 29.1 | 182.5 ± 13.5
Week 16 | 307.8 ± 67.5 | 308.6 ± 60.7 | 216.5 ± 35.5 | 270.2 ± 56.9
Week 26 | 185.9 ± 22.4 | 131.0 ± 23.4 | 118.5 ± 7.5 | 148.9 ± 12.8
Week 39 | 127.6 ± 17.1 | 182.7 ± 29.0 | 238.0 ± 39.8* | 755.0 ± 88.4**
Lymphocytes (%)
Week 4 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.163 ± 0.125
Week 16 | 0.038 ± 0.038 | 0.238 ± 0.121 | 0.213 ± 0.113 | 1.125 ± 0.397**
Week 26 | 0.000 ± 0.000 | 0.513 ± 0.205 | 0.588 ± 0.163** | 1.138 ± 0.235**
Week 39 | 0.075 ± 0.049 | 0.613 ± 0.288 | 1.300 ± 0.306** | 0.713 ± 0.215
Absolute Lymphocytes (#/µL)
Week 4 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0388 ± 0.282
Week 16 | 0.100 ± 0.100 | 0.613 ± 0.361 | 1.013 ± 0.611 | 5.850 ± 2.092**
Week 26 | 0.000 ± 0.000 | 0.775 ± 0.291* | 1.625 ± 0.448** | 5.425 ± 1.350**
Week 39 | 0.113 ± 0.074 | 3.013 ± 1.943 | 5.663 ± 1.557** | 11.663 ± 3.723**
Neutrophils (%)
Week 4 | 0.450 ± 0.154 | 0.375 ± 0.209 | 7.250 ± 2.069** | 37.913 ± 3.405**
Week 16 | 0.075 ± 0.049 | 24.213 ± 3.419** | 50.125 ± 2.935** | 47.700 ± 4.788**
Week 26 | 0.200 ± 0.089 | 29.625 ± 3.159** | 50.750 ± 4.756** | 65.538 ± 3.461**
Week 39 | 0.325 ± 0.164 | 42.375 ± 4.191** | 45.288 ± 4.850** | 55.700 ± 4.975**
Absolute Neutrophils (#/µL)
Week 4 | 0.950 ± 0.271 | 0.850 ± 0.385 | 20.563 ± 7.392** | 118.463 ± 20.735**
Week 16 | 0.188 ± 0.123 | 102.963 ± 27.692** | 221.288 ± 42.081** | 255.875 ± 37.469**
Week 26 | 0.338 ± 0.129 | 52.588 ± 7.867** | 142.350 ± 27.283** | 312.600 ± 45.920**
Week 39 | 0.463 ± 0.221 | 153.113 ± 39.785** | 206.413 ± 38.182** | 1,082.09 ± 237.138**
Eosinophils (%)
Week 4 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 16 | 0.000 ± 0.000 | 0.075 ± 0.049 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 26 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 39 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Absolute Eosinophils (#/µL)
Week 4 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 16 | 0.000 ± 0.000 | 0.300 ± 0.237 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 26 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 39 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Lactate Dehydrogenase (IU/L)
Week 4 | 34 ± 8 | 36 ± 4 | 40 ± 5 | 93 ± 7**
Week 16 | 31 ± 7 | 63 ± 6* | 104 ± 7** | 162 ± 16**
Week 26 | 36 ± 6 | 87 ± 7** | 160 ± 21** | 322 ± 26**
Week 39 | 19 ± 6 | 104 ± 29** | 144 ± 26** | 338 ± 24**
Albumin (g/dL)
Week 4 | 0.01 ± 0.01 | 0.01 ± 0.01 | 0.02 ± 0.01 | 0.02 ± 0.01
Week 16 | 0.02 ± 0.01 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Week 26 | 0.03 ± 0.01 | 0.03 ± 0.01 | 0.02 ± 0.01 | 0.03 ± 0.02
Week 39 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Female
Viable Cells (%)
Week 4 | 89.31 ± 1.66 | 90.10 ± 1.90 | 90.46 ± 0.66 | 91.35 ± 1.99
Week 26 | 86.49 ± 2.93 | 89.69 ± 2.20 | 90.00 ± 1.79 | 90.90 ± 1.83
Total Cells Counted
Week 4 | 446.9 ± 30.9 | 398.8 ± 24.2 | 403.1 ± 38.5 | 311.3 ± 24.6**
Week 26 | 294.4 ± 21.6 | 298.8 ± 31.4 | 592.5 ± 49.1** | 768.1 ± 30.3**
Macrophages (%)
Week 4 | 99.7 ± 0.1 | 99.8 ± 0.1 | 98.3 ± 0.5* | 72.2 ± 5.9**
Week 26 | 99.4 ± 0.3 | 53.1 ± 4.0** | 34.2 ± 3.5** | 27.3 ± 2.8**
Absolute Macrophages (#/µL)
Week 4 | 445.6 ± 31.1 | 397.9 ± 24.5 | 396.2 ± 37.5 | 222.1 ± 24.4**
Week 26 | 292.4 ± 21.0 | 158.1 ± 20.0** | 196.8 ± 17.9* | 207.7 ± 21.2
Lymphocytes (%)
Week 4 | 0.163 ± 0.091 | 0.038 ± 0.038 | 0.363 ± 0.082 | 0.650 ± 0.155**
Week 26 | 0.038 ± 0.038 | 0.250 ± 0.109 | 0.413 ± 0.091** | 0.200 ± 0.089
Absolute Lymphocytes (#/µL)
Week 4 | 0.650 ± 0.358 | 0.125 ± 0.125 | 1.575 ± 0.296* | 2.138 ± 0.523*
Week 26 | 0.138 ± 0.138 | 0.688 ± 0.271 | 2.538 ± 0.554** | 1.675 ± 0.734*
Neutrophils (%)
Week 4 | 0.150 ± 0.057 | 0.075 ± 0.049 | 0.963 ± 0.364 | 30.913 ± 5.685**
Week 26 | 0.538 ± 0.285 | 46.663 ± 4.075** | 65.363 ± 3.427** | 72.538 ± 2.769**
Absolute Neutrophils (#/µL)
Week 4 | 0.663 ± 0.256 | 0.325 ± 0.220 | 3.938 ± 1.834 | 92.838 ± 17.475**
Week 26 | 1.800 ± 0.962 | 139.988 ± 21.328** | 393.200 ± 46.620** | 558.775 ± 34.693**
Eosinophils (%)
Week 4 | 0.000 ± 0.000 | 0.125 ± 0.090 | 0.363 ± 0.240 | 0.375 ± 0.209
Week 26 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Absolute Eosinophils (#/µL)
Week 4 | 0.000 ± 0.000 | 0.413 ± 0.297 | 1.413 ± 0.964 | 1.250 ± 0.715
Week 26 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Lactate Dehydrogenase (IU/L)
Week 4 | 34 ± 4 | 30 ± 2 | 37 ± 4 | 67 ± 11**
Week 26 | 26 ± 2 | 87 ± 12** | 235 ± 27** | 420 ± 20**
Albumin (g/dL)
Week 4 | 0.01 ± 0.01 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.01 ± 0.01
Week 26 | 0.06 ± 0.02 | 0.10 ± 0.01 | 0.07 ± 0.01 | 0.05 ± 0.01

* Significantly different (p ≤ 0.05) from the chamber control group by Dunn’s or Shirley’s test.

** p ≤ 0.01.

^a^ Data are presented as mean ± standard error.

Lung burdens of blasting sand were approximately 5, 10, and 15 mg blasting sand/g lung in the 15, 30, and 60 mg/m^3^ male rats, respectively, at 39 weeks and did not reach steady-state levels (Table B-16). Normalized lung burdens and calculated deposition rates for blasting sand were proportional to exposure concentrations (Table B-16 and Table B-19). The calculated lung deposition rates were 46, 98, and 172 μg/blasting sand/total lung per day, and the calculated lung clearance half-lives were 207, 271, and 848 days in groups exposed to 15, 30, and 60 mg/m^3^ blasting sand, respectively (Table B-19). Generally, blasting sand burdens in bronchial lymph nodes were greater than in mediastinal lymph nodes, however, they were both quite variable (Table B-17 and Table B-18). Due to the large blasting sand lung burdens, high deposition rates, and long lung clearance half-lives, the lung burdens were evaluated for possible lung overload (Table B-20). Lung overload is assumed to begin when the volume of blasting sand in the lung reaches a threshold volume equal to approximately 6% of the volume of the total lung alveolar macrophage pool.^72^ This condition was first reached at 137, 55, and 30 days in the 15, 30, and 60 mg/m^3^ groups, respectively. By the end of the study, lung blasting sand volumes exceeded the threshold for overload by factors of 1.6, 3.8, and 8.4 for the 15, 30, and 60 mg/m^3^ groups, respectively (Table B-20). Tissue burdens of blasting sand, although quite large, were proportional to exposure concentration in the lungs but were quite variable in the lymph nodes. The large lung burdens, the long lung half-lives, and the magnitude by which 6% of the alveolar macrophage lung volume was exceeded by the end of the study collectively indicated that lung overload conditions were reached for blasting sand at all exposure concentrations tested.

No test article-related gross lesions were observed at necropsy in any of the exposed groups. Test article-related nonneoplastic lesions occurred in the lung, larynx, nose, and bronchial and mediastinal lymph nodes (Table 9).

Table 9 Incidences of Selected Nonneoplastic Lesions in Male Sprague Dawley Rats in the 39-week Inhalation Study of Blasting Sand

| Chamber Control | 15 mg/m^3^ | 30 mg/m^3^ | 60 mg/m^3^
Four-week Interim Evaluation
Nose^a^ | 8 | 8 | 8 | 8
Olfactory epithelium, accumulation, hyaline droplet^b^ | 0 | 2 (1.0)^c^ | 3 (1.1) | 2 (1.0)
Lung | 8 | 8 | 8 | 8
Infiltration cellular, histiocyte | 1 (1.0) | 1 (1.0) | 4 (1.0) | 8** (1.0)
Inflammation, chronic active | 0 | 2 (1.0) | 2 (1.0) | 3 (1.0)
Foreign body material | 0 | 8** | 8** | 8**
Alveolar epithelium, hyperplasia, focal | 0 | 0 | 0 | 1 (3.0)
16-week Interim Evaluation
Nose | 8 | 8 | 8 | 8
Olfactory epithelium, accumulation, hyaline droplet | 8 (1.0) | 8 (1.6) | 8 (1.4) | 8 (2.4)
Respiratory epithelium, accumulation, hyaline droplet | 0 | 8** (1.0) | 8** (1.3) | 7** (1.1)
Lung | 8 | 8 | 8 | 8
Infiltration cellular, histiocyte | 2 (1.0) | 8** (1.4) | 8** (2.0) | 8** (2.0)
Inflammation, chronic active | 1 (1.0) | 3 (1.0) | 3 (1.0) | 8** (1.0)
Foreign body material | 0 | 8** | 8** | 8**
Lymph Node, Bronchial | 5 | 7 | 8 | 8
Foreign body material | 0 | 7** | 8** | 7**
Infiltration cellular, histiocyte | 0 | 7** (1.0) | 8** (1.5) | 7** (1.4)
Lymph Node, Mediastinal | 8 | 6 | 8 | 8
Foreign body material | 0 | 5** | 5* | 8**
Infiltration cellular, histiocyte | 0 | 5** (2.2) | 5* (2.4) | 8** (3.0)
26-week Interim Evaluation
Nose | 8 | 8 | 8 | 8
Olfactory epithelium, accumulation, hyaline droplet | 8 (1.9) | 8 (2.8) | 8 (2.9) | 8 (2.6)
Respiratory epithelium, accumulation, hyaline droplet | 6 (1.0) | 8 (1.0) | 8 (1.1) | 8 (1.0)
Lung | 8 | 8 | 8 | 8
Infiltration cellular, histiocyte | 4 (1.0) | 8* (1.5) | 8* (1.8) | 8* (2.1)
Inflammation, chronic active | 2 (1.0) | 7* (1.0) | 7* (1.0) | 8** (1.0)
Interstitium, fibrosis | 0 | 8** (1.0) | 7** (1.0) | 8** (1.6)
Foreign body material | 0 | 8** | 8** | 8**
Proteinosis | 0 | 0 | 0 | 1 (1.0)
Alveolar epithelium, hyperplasia | 0 | 8** (1.0) | 8** (1.0) | 8** (1.0)
Lymph Node, Bronchial | 7 | 8 | 8 | 8
Foreign body material | 0 | 6** | 5* | 8**
Infiltration cellular, histiocyte | 0 | 6** (1.3) | 5* (2.0) | 8** (2.1)
Fibrosis | 0 | 0 | 1 (1.0) | 1 (1.0)
Lymph Node, Mediastinal | 8 | 8 | 7 | 7
Foreign body material | 0 | 6** | 7** | 7**
Infiltration cellular, histiocyte | 0 | 6** (2.7) | 7** (3.0) | 7** (3.1)
Fibrosis | 0 | 0 | 0 | 2 (1.5)
39-week Evaluation
Nose | 8 | 8 | 8 | 8
Olfactory epithelium, accumulation, hyaline droplet | 8 (1.6) | 8 (3.1) | 8 (3.5) | 8 (3.4)
Respiratory epithelium, accumulation, hyaline droplet | 6 (1.0) | 8 (1.0) | 8 (1.3) | 8 (1.0)
Larynx | 8 | 8 | 8 | 8
Epiglottis, metaplasia, squamous | 0 | 1 (1.0) | 1 (1.0) | 1 (1.0)
Lung | 8 | 8 | 8 | 8
Infiltration cellular, histiocyte | 4 (1.0) | 8* (1.5) | 8* (2.4) | 8** (3.0)
Inflammation, chronic active | 2 (1.0) | 8** (1.0) | 8** (1.1) | 8** (1.6)
Interstitium, fibrosis | 0 | 8** (1.0) | 8** (1.0) | 8** (2.0)
Foreign body material | 0 | 8** | 8** | 8**
Proteinosis | 0 | 0 | 0 | 6** (1.3)
Alveolar epithelial, hyperplasia | 0 | 8** (1.0) | 8** (2.0) | 8** (2.0)
Alveolar epithelial, hyperplasia, focal | 0 | 0 | 0 | 1 (4.0)
Lymph node, bronchial | 7 | 5 | 7 | 8
Foreign body material | 0 | 3* | 6** | 7**
Infiltration cellular, histiocyte | 0 | 3* (1.7) | 6** (1.3) | 7** (2.1)
Fibrosis | 0 | 0 | 0 | 2 (1.0)
Lymph node, mediastinal | 7 | 8 | 8 | 8
Foreign body material | 0 | 8** | 8** | 8**
Infiltration cellular, histiocyte | 0 | 8** (3.0) | 8** (4.0) | 8** (4.0)
Fibrosis | 0 | 1 (1.0) | 1 (2.0) | 2 (2.0)
Necrosis | 0 | 0 | 0 | 1 (1.0)

* Significantly different (p ≤ 0.05) from the chamber control group by the Fisher exact test.

** p ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Exposure-related lesions in the lung included histiocytic cellular infiltration, chronic active inflammation, interstitial fibrosis, foreign bodies (presumably the test article), proteinosis, and alveolar epithelial hyperplasia (Table 9).^70,71^ The incidence of histiocytic cellular infiltration was significantly increased beginning at week 4 in the 60 mg/m^3^ group and at week 16 in the 15 and 30 mg/m^3^ groups compared to the chamber control incidence; severity of the lesion tended to increase with exposure concentration and duration. The incidence of chronic active inflammation was significantly increased in the 60 mg/m^3^ group beginning at week 16 and in the 15 and 30 mg/m^3^ groups beginning at week 26. Histiocytic cellular infiltration was characterized by increased numbers of alveolar macrophages within the alveoli. Many of the macrophages, particularly at the higher exposure concentrations, contained fine intracytoplasmic foreign bodies (granular material), presumably the test material. Chronic active inflammation was diagnosed when the increased numbers of macrophages were accompanied by scattered neutrophils and/or lymphocytes. With longer exposure duration and greater exposure concentration, the alveolar septa were often thickened by mononuclear inflammatory cells, fibrosis, and alveolar epithelial hyperplasia. Most of these lesions were graded according to the following scale: minimal: ≤5%; mild: greater than 5% but ≤35%; moderate: greater than 35% but ≤65%; and marked: greater than 65% of alveoli affected. Alveolar epithelial hyperplasia was considered minimal when less than 10% of alveolar spaces were lined by hyperplastic pneumocytes and mild when 10–30% of alveolar spaces were lined by hyperplastic pneumocytes.

The incidence of minimal to mild interstitial fibrosis was significantly increased in all exposed groups at weeks 26 and 39 compared to the chamber control group incidence (Table 9). Fibrosis was typically seen in areas also affected by chronic active inflammation, histiocytic cellular infiltration, or alveolar epithelium hyperplasia. Interstitium fibrosis was characterized by an increase in lacey collagen fibers in the alveolar septa. Masson’s Trichrome staining was used to confirm the presence of interstitial fibrosis (Figure 2).

Figure 2

Pulmonary Interstitial Fibrosis in a Male Rat Administered 60 mg/m^3^ Blasting Sand by Whole Body Inhalation for 39 Weeks (Masson’s Trichrome Stain)

The blue staining in the interalveolar septa is collagen, consistent with interstitial fibrosis.

All exposed male rats had foreign body material in the lung; this lesion was not seen in any chamber control rat (Table 9). Foreign bodies were characterized by a fine, golden-brown, granular material within the cytoplasm of alveolar macrophages or free within the alveolar spaces. The number of macrophages containing the material increased with increasing exposure concentration. The absence of the material in chamber control rats, the positive correlation between exposure concentration and the amount of the material present, and the morphological appearance of the material were consistent with the material being blasting sand.

Alveolar proteinosis was observed in one 60 mg/m^3^ rat at week 26 and six 60 mg/m^3^ rats at week 39, and the severity was slightly increased at week 39 (Table 9). Proteinosis was characterized by the presence of amorphous eosinophilic material within the alveolar spaces, often with fine, granular, golden-brown material, assumed to be foreign bodies.

Alveolar epithelial hyperplasia occurred in the lung of all exposed rats beginning at week 26 (Table 9). Most of these lesions were associated with chronic active inflammation and were indicative of a regenerative response of alveolar epithelium cells (Figure 3, Figure 4). Two animals in the 60 mg/m^3^ group (one at 4 weeks and one at the end of the study) had focal alveolar epithelial hyperplasia that was not associated with inflammation (Figure 5). Alveolar epithelial hyperplasia was characterized by cuboidal cells lining the alveolar septa in areas with inflammation. With more severe inflammation, the cuboidal alveolar epithelium cells were closely packed, and they were more sparsely distributed in areas with less severe inflammation. Focal alveolar epithelial hyperplasia had a similar appearance but occurred in areas with no inflammation, and the lesion was better demarcated than alveolar epithelial hyperplasia. Neither form of the lesion caused compression of adjacent tissue.

Figure 3

Alveolar Epithelial Hyperplasia in a Male Rat Administered 60 mg/m^3^ Blasting Sand by Whole Body Inhalation for 39 Weeks (H&E)

This form of alveolar epithelial hyperplasia, which accompanies inflammation in the lung, is thought to be secondary to inflammation and alveolar epithelial damage.

Figure 4

Alveolar Epithelial Hyperplasia in a Male Rat Administered 60 mg/m^3^ Blasting Sand by Whole Body Inhalation for 39 Weeks (H&E)

This is a higher magnification image of Figure 3.

Figure 5

Focal Alveolar Epithelial Hyperplasia in a Male Rat Administered 60 mg/m^3^ Blasting Sand by Whole Body Inhalation for 39 Weeks (H&E)

This well-circumscribed area of alveolar epithelial hyperplasia is thought to be on a continuum with alveolar/bronchiolar neoplasia. Note the lack of accompanying inflammation.

In the larynx at 39 weeks, squamous metaplasia of the epithelium at the base of the epiglottis occurred in one rat from each exposed group (Table 9). This lesion rarely occurs as a background lesion and is the most common induced laryngeal lesion seen in inhalation studies. Therefore, although the incidence in any of the exposed groups was not significantly increased compared to that in the chamber control group, the occurrences of the lesion were considered exposure related. Squamous metaplasia of the laryngeal epithelium was characterized by replacement of the normally cuboidal epithelium by flattened and elongated epithelial cells.

Accumulations of hyaline droplets in the olfactory and respiratory epithelium were the only exposure-related lesions that occurred in the nose (Table 9). Although hyaline droplets are commonly seen in control animals, they can increase in size and have a greater distribution with exposure to various chemicals or particulates in inhalation studies. Hyaline droplet accumulation in the olfactory epithelium occurred in all rats, including chamber control animals, beginning at week 16, and the severity of the lesions increased with increasing exposure duration. The incidence of hyaline droplet accumulation in the respiratory epithelium was significantly increased in all exposed groups at 16 weeks, compared to the chamber control group incidence. Hyaline droplet accumulation in the olfactory and respiratory epithelium was noted primarily at Levels II and III of the nose and consisted of brightly eosinophilic intracytoplasmic globules that occasionally distorted cells and displaced nuclei. Locations commonly affected were the septum and dorsal meatus of Level II at the junction of the respiratory and olfactory epithelium and the ventral ethmoturbinates and, less often, the dorsal ethmoturbinates of Level III.

Exposure-related lesions in the bronchial and mediastinal lymph nodes included foreign bodies, histiocytic cellular infiltration, and fibrosis (Table 9). There was also necrosis in the mediastinal lymph node of one 60 mg/m^3^ rat at the end of the study.

The presence of foreign body material and histiocytic cellular infiltration in the bronchial and mediastinal lymph nodes of all exposed groups were significantly greater than those of the chamber control group beginning at week 16 (Table 9). In general, the severity of histiocytic cellular infiltration increased with increasing exposure concentration. Foreign body material and histiocytic cellular infiltration in the lymph nodes were morphologically similar to those lesions seen in the lung. Histiocytic cellular infiltration was characterized by increased numbers of macrophages within the sinuses and, scattered amid the lymphocytes, in the cortex and paracortex. Nearly all these macrophages contained fine, golden-brown to brown foreign bodies (granular material) within the cytoplasm. All the macrophages and foreign body material were presumed to have migrated to the lymph nodes from the lungs.

Minimal to mild fibrosis occurred in the bronchial and mediastinal lymph nodes of a few exposed rats beginning at week 26 (Table 9). The severity of the lesion in the mediastinal lymph node generally increased with increasing exposure concentration. Fibrosis was characterized by an increase in eosinophilic material (consistent with collagen) in the lymph node. Additionally, minimal necrosis, characterized by loss of cells and the presence of cellular debris, was present in an area of fibrosis in one rat from the 60 mg/m^3^ group at 39 weeks.

### Specular Hematite

Two male rats, one chamber control and one exposed to 60 mg/m^3^, were removed from the study during week 37 for reasons unrelated to exposure to the test article; mean body weights of all exposed groups were similar to those of the chamber control group throughout the study (Table 10 and Figure 6. No clinical observations were associated with exposure to specular hematite.

Table 10 Mean Body Weights and Survival of Male Sprague Dawley Rats in the 39-week Inhalation Study of Specular Hematite

Day | 0 mg/m^3^ | | 15 mg/m^3^ | | | 30 mg/m^3^ | | | 60 mg/m^3^
Day | Av. Wt. (g) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors | Av. Wt. (g) | Wt. (% of Controls) | No. of Survivors
1 | 123 | 62 | 122 | 99 | 62 | 123 | 100 | 62 | 121 | 98 | 62
8^a^ | 169 | 57 | 169 | 100 | 57 | 170 | 100 | 57 | 168 | 99 | 57
16 | 220 | 57 | 220 | 100 | 57 | 222 | 101 | 57 | 219 | 100 | 57
23 | 257 | 57 | 258 | 100 | 57 | 263 | 102 | 57 | 259 | 101 | 57
30^a^ | 282 | 44 | 287 | 102 | 44 | 292 | 103 | 44 | 288 | 102 | 44
37 | 301 | 44 | 306 | 102 | 44 | 313 | 104 | 44 | 308 | 102 | 44
44 | 320 | 44 | 326 | 102 | 44 | 331 | 103 | 44 | 328 | 103 | 44
51 | 337 | 44 | 342 | 101 | 44 | 347 | 103 | 44 | 345 | 102 | 44
58^a^ | 350 | 39 | 352 | 101 | 39 | 361 | 103 | 39 | 359 | 103 | 39
65 | 361 | 39 | 365 | 101 | 39 | 373 | 103 | 39 | 370 | 103 | 39
72 | 373 | 39 | 376 | 101 | 39 | 384 | 103 | 39 | 380 | 102 | 39
79 | 381 | 39 | 385 | 101 | 39 | 394 | 103 | 39 | 392 | 103 | 39
86 | 391 | 39 | 394 | 101 | 39 | 403 | 103 | 39 | 401 | 103 | 39
93 | 398 | 39 | 401 | 101 | 39 | 411 | 103 | 39 | 409 | 103 | 39
100 | 406 | 39 | 410 | 101 | 39 | 418 | 103 | 39 | 416 | 103 | 39
107 | 413 | 39 | 414 | 100 | 39 | 424 | 103 | 39 | 423 | 102 | 39
135^a^ | 439 | 26 | 435 | 99 | 26 | 442 | 101 | 26 | 445 | 101 | 26
163 | 457 | 26 | 452 | 99 | 26 | 461 | 101 | 26 | 465 | 102 | 26
191^a^ | 470 | 13 | 473 | 101 | 13 | 488 | 104 | 13 | 466 | 99 | 13
219 | 488 | 13 | 492 | 101 | 13 | 501 | 103 | 13 | 481 | 99 | 13
248 | 501 | 13 | 507 | 101 | 13 | 512 | 102 | 13 | 496 | 99 | 13

^a^ Interim evaluations occurred during weeks 1, 4, 8, 16, and 26.

Figure 6

Growth Curves for Male Sprague Dawley Rats Exposed to Specular Hematite by Inhalation for 39 Weeks

Lungs and bronchial and mediastinal lymph nodes were weighed in male rats used for tissue burden analyses. Compared to those in the chamber control group, the absolute and relative lung weights were significantly increased in the 30 and 60 mg/m^3^ groups at weeks 16, 26, and 39 (Table 11). Absolute and relative bronchial lymph node weights were significantly increased at weeks 16, 26, and 39 in the 60 mg/m^3^ group and at week 26 in the 30 mg/m^3^ group. The absolute and relative mediastinal lymph node weights were significantly increased at weeks 16 and 26 in the 60 mg/m^3^ group but not at week 39.

Table 11 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Male Sprague Dawley Tissue Burden Rats in the 39-week Inhalation Study of Specular Hematite^a^

| Chamber Control | 15 mg/m^3^ | 30 mg/m^3^ | 60 mg/m^3^
Week 1
n | 5 | 5 | 5 | 5
Body Wt. | 146 ± 5 | 140 ± 4 | 144 ± 4 | 144 ± 7
Lung
Absolute | 0.93 ± 0.02 | 0.87 ± 0.01 | 0.91 ± 0.03 | 0.87 ± 0.03
Relative | 6.34 ± 0.09 | 6.24 ± 0.20 | 6.34 ± 0.17 | 6.08 ± 0.15
Bronchial Lymph Node
Absolute | 0.010 ± 0.002 | 0.011 ± 0.003 | 0.016 ± 0.003 | 0.011 ± 0.002
Relative | 0.07 ± 0.01 | 0.08 ± 0.02 | 0.11 ± 0.02 | 0.08 ± 0.01
Mediastinal Lymph Node
Absolute | 0.018 ± 0.005 | 0.021 ± 0.003 | 0.026 ± 0.003 | 0.019 ± 0.001
Relative | 0.13 ± 0.03 | 0.15 ± 0.02 | 0.18 ± 0.02 | 0.13 ± 0.00
Week 4
n | 5 | 5 | 5 | 5
Body Wt. | 263 ± 8 | 273 ± 9 | 270 ± 8 | 266 ± 6
Lung
Absolute | 1.15 ± 0.03 | 1.16 ± 0.03 | 1.18 ± 0.04 | 1.17 ± 0.03
Relative | 4.37 ± 0.05 | 4.27 ± 0.06 | 4.37 ± 0.08 | 4.41 ± 0.05
Bronchial Lymph Node
Absolute | 0.026 ± 0.005 | 0.010 ± 0.003 | 0.020 ± 0.006 | 0.021 ± 0.004
Relative | 0.10 ± 0.02 | 0.04 ± 0.01* | 0.07 ± 0.02 | 0.08 ± 0.01
Mediastinal Lymph Node
Absolute | 0.025 ± 0.003 | 0.024 ± 0.005 | 0.027 ± 0.005 | 0.023 ± 0.003
Relative | 0.10 ± 0.01 | 0.09 ± 0.02 | 0.10 ± 0.02 | 0.08 ± 0.01
Week 8
n | 5 | 5 | 5 | 5
Body Wt. | 339 ± 13 | 365 ± 8 | 357 ± 12 | 344 ± 11
Lung
Absolute | 1.30 ± 0.05 | 1.35 ± 0.06 | 1.36 ± 0.06 | 1.40 ± 0.03
Relative | 3.85 ± 0.12 | 3.68 ± 0.09 | 3.81 ± 0.06 | 4.09 ± 0.09
Bronchial Lymph Node
Absolute | 0.019 ± 0.003 | 0.020 ± 0.003 | 0.031 ± 0.004 | 0.028 ± 0.006
Relative | 0.06 ± 0.01 | 0.05 ± 0.01 | 0.09 ± 0.01 | 0.08 ± 0.02
Mediastinal Lymph Node
Absolute | 0.025 ± 0.004 | 0.025 ± 0.002 | 0.026 ± 0.005 | 0.035 ± 0.008
Relative | 0.07 ± 0.01 | 0.07 ± 0.01 | 0.07 ± 0.01 | 0.10 ± 0.02
Week 16
n | 5 | 5 | 5 | 5
Body Wt. | 406 ± 8 | 418 ± 4 | 436 ± 13 | 412 ± 11
Lung
Absolute | 1.31 ± 0.04 | 1.44 ± 0.03* | 1.55 ± 0.04** | 1.56 ± 0.04**
Relative | 3.24 ± 0.10 | 3.44 ± 0.07 | 3.56 ± 0.03** | 3.80 ± 0.06**
Bronchial Lymph Node
Absolute | 0.014 ± 0.003 | 0.015 ± 0.003 | 0.027 ± 0.004 | 0.036 ± 0.007**
Relative | 0.04 ± 0.01 | 0.04 ± 0.01 | 0.06 ± 0.01 | 0.09 ± 0.02**
Mediastinal Lymph Node
Absolute | 0.019 ± 0.002 | 0.020 ± 0.003 | 0.029 ± 0.004 | 0.034 ± 0.005*
Relative | 0.05 ± 0.01 | 0.05 ± 0.01 | 0.07 ± 0.01 | 0.08 ± 0.01*
Week 26
n | 5 | 5 | 5 | 5
Body Wt. | 453 ± 13 | 456 ± 15 | 451 ± 7 | 492 ± 11
Lung
Absolute | 1.48 ± 0.04 | 1.52 ± 0.05 | 1.67 ± 0.04* | 1.96 ± 0.05**
Relative | 3.28 ± 0.12 | 3.34 ± 0.06 | 3.70 ± 0.10* | 3.99 ± 0.15**
Bronchial Lymph Node
Absolute | 0.013 ± 0.002 | 0.023 ± 0.005 | 0.040 ± 0.004** | 0.050 ± 0.006**
Relative | 0.03 ± 0.01 | 0.05 ± 0.01 | 0.09 ± 0.01** | 0.10 ± 0.01**
Mediastinal Lymph Node
Absolute | 0.019 ± 0.004 | 0.032 ± 0.007 | 0.030 ± 0.002 | 0.046 ± 0.002**
Relative | 0.04 ± 0.01 | 0.07 ± 0.01 | 0.07 ± 0.00 | 0.09 ± 0.01**
Week 39
n | 4 | 5 | 5 | 4
Body Wt. | 499 ± 13 | 520 ± 26 | 501 ± 12 | 485 ± 8
Lung
Absolute | 1.51 ± 0.07 | 1.62 ± 0.03 | 1.76 ± 0.05** | 2.11 ± 0.05**
Relative | 3.03 ± 0.17 | 3.15 ± 0.14 | 3.52 ± 0.04** | 4.35 ± 0.03**
Bronchial Lymph Node
Absolute | 0.017 ± 0.006 | 0.025 ± 0.005 | 0.041 ± 0.005 | 0.051 ± 0.014*
Relative | 0.03 ± 0.01 | 0.05 ± 0.01 | 0.08 ± 0.01 | 0.11 ± 0.03*
Mediastinal Lymph Node
Absolute | 0.033 ± 0.009 | 0.031 ± 0.011 | 0.031 ± 0.006 | 0.060 ± 0.011
Relative | 0.07 ± 0.02 | 0.06 ± 0.02 | 0.06 ± 0.01 | 0.12 ± 0.02

* Significantly different (p ≤ 0.05) from the chamber control group by the Dunnett or Williams tests.

** p ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

The greatest changes in measured BAL fluid parameters after specular hematite exposure occurred in neutrophils, lymphocytes, and lactate dehydrogenase (LDH) activity (Table 12 and Table A-2). Absolute numbers of neutrophils and lymphocytes and LDH activity were significantly increased in BAL fluid of core male rats, mostly at week 39 at the 60 mg/m^3^ specular hematite exposure concentration compared to the chamber control group. The changes in the exposed groups generally increased in magnitude with exposure concentration and time, with the 60 mg/m^3^ group often being most severely affected. Numerous statistical differences in BAL fluid composition occurred between exposed and chamber control groups (increased percentages of lymphocytes and neutrophils, decreased percentage of alveolar macrophages) that were consistent with cells (mainly neutrophils and a small number of lymphocytes) infiltrating the lung in response to specular hematite exposure. For males, all these changes were present in all exposed groups at weeks 16, 26, and 39 (except increased lymphocytes at week 26); for females, these changes were present in all exposed groups at week 26. In addition, at week 4, the 60 mg/m^3^ groups exhibited increased lymphocytes (females), decreased macrophage percentage (males), and increased neutrophil percentage (males). BAL fluid composition assessments also revealed exposure-induced cytotoxic lung injury with increased lactate dehydrogenase activities in all exposed groups of males beginning at week 16, and in all exposed groups of females at week 26.

Table 12 Bronchoalveolar Lavage Data for Sprague Dawley Rats in the 39-week Inhalation Study of Specular Hematite^a^

| Chamber Control | 15 mg/m^3^ | 30 mg/m^3^ | 60 mg/m^3^
Male
Week 4 | 8 | 8 | 8 | 8
Week 16 | 7 | 8 | 7 | 6
Week 26 | 8 | 8 | 8 | 8
Week 39 | 8 | 8 | 8 | 8
Viable Cells (%)
Week 4 | 81.76 ± 3.80 | 86.33 ± 3.33 | 87.74 ± 2.17 | 91.41 ± 1.67
Week 16 | 88.67 ± 0.52 | 91.03 ± 1.74 | 87.97 ± 1.91 | 92.95 ± 2.40
Week 26 | 93.03 ± 1.20 | 94.41 ± 1.26 | 98.19 ± 0.74** | 98.35 ± 0.60**
Week 39 | 89.75 ± 2.29 | 94.53 ± 1.82 | 97.35 ± 0.90* | 98.96 ± 0.39**
Total Cells Counted
Week 4 | 153.1 ± 22.1 | 198.1 ± 23.0 | 186.9 ± 24.0 | 155.6 ± 18.1
Week 16 | 554 ± 61.0 | 371 ± 42.0 | 313 ± 36.0** | 391 ± 28.0
Week 26 | 204.4 ± 18.9 | 192.5 ± 17.2 | 280.6 ± 27.6* | 608.1 ± 83.4**
Week 39 | 173 ± 11.0 | 273 ± 27.0* | 394 ± 51.0** | 749 ± 46.0**
Macrophages (%)
Week 4 | 99.7 ± 0.1 | 99.7 ± 0.2 | 99.2 ± 0.2 | 96.1 ± 0.8**
Week 16 | 99.7 ± 0.1 | 90.7 ± 2.1** | 78.6 ± 3.0** | 48.0 ± 3.6**
Week 26 | 99.9 ± 0.1 | 91.0 ± 1.8** | 73.7 ± 3.7** | 44.4 ± 2.4**
Week 39 | 99.8 ± 0.1 | 87.2 ± 2.4** | 65.1 ± 3.7** | 34.9 ± 4.3**
Absolute Macrophages (#/µL)
Week 4 | 152.6 ± 22.1 | 197.8 ± 23.2 | 185.3 ± 23.6 | 150.2 ± 18.6
Week 16 | 552.0 ± 60.9 | 334.8 ± 37.1* | 244.7 ± 30.4** | 188.5 ± 21.4**
Week 26 | 204.2 ± 19.0 | 173.7 ± 13.8 | 206.2 ± 22.5 | 273.4 ± 45.1
Week 39 | 172.8 ± 11.4 | 233.7 ± 18.2 | 252.0 ± 31.7 | 270.7 ± 44.3
Lymphocytes (%)
Week 4 | 0.200 ± 0.089 | 0.125 ± 0.125 | 0.413 ± 0.126 | 0.413 ± 0.126
Week 16 | 0.043 ± 0.043 | 0.838 ± 0.191** | 0.671 ± 0.148** | 1.733 ± 0.429**
Week 26 | 0.038 ± 0.038 | 0.000 ± 0.000 | 0.038 ± 0.038 | 0.038 ± 0.038
Week 39 | 0.000 ± 0.000 | 0.838 ± 0.328** | 1.463 ± 0.272** | 1.675 ± 0.351**
Absolute Lymphocytes (#/µL)
Week 4 | 0.288 ± 0.109 | 0.138 ± 0.138 | 0.838 ± 0.345 | 0.563 ± 0.148
Week 16 | 0.314 ± 0.314 | 3.150 ± 0.840* | 2.329 ± 0.637* | 6.350 ± 1.358**
Week 26 | 0.063 ± 0.063 | 0.000 ± 0.000 | 0.188 ± 0.188 | 0.263 ± 0.263
Week 39 | 0.000 ± 0.000 | 2.675 ± 1.281** | 5.500 ± 1.104** | 11.850 ± 2.142**
Neutrophils (%)
Week 4 | 0.125 ± 0.090 | 0.163 ± 0.091 | 0.375 ± 0.171 | 3.500 ± 0.721**
Week 16 | 0.286 ± 0.155 | 8.450 ± 1.943** | 20.743 ± 2.993** | 50.217 ± 3.741**
Week 26 | 0.088 ± 0.088 | 9.050 ± 1.772** | 26.313 ± 3.735** | 55.613 ± 2.385**
Week 39 | 0.188 ± 0.055 | 11.925 ± 2.173** | 33.550 ± 3.733** | 63.425 ± 4.085**
Absolute Neutrophils (#/µL)
Week 4 | 0.238 ± 0.169 | 0.200 ± 0.102 | 0.750 ± 0.351 | 4.900 ± 0.992**
Week 16 | 1.257 ± 0.647 | 32.700 ± 8.403** | 65.786 ± 13.558** | 195.767 ± 19.181**
Week 26 | 0.113 ± 0.113 | 18.788 ± 4.945** | 74.250 ± 12.106** | 334.488 ± 43.107**
Week 39 | 0.363 ± 0.112 | 36.175 ± 9.806** | 137.063 ± 32.091** | 466.263 ± 26.946**
Eosinophils (%)
Week 4 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 16 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.050 ± 0.050
Week 26 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 39 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Absolute Eosinophils (#/µL)
Week 4 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 16 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.250 ± 0.250
Week 26 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 39 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Lactate Dehydrogenase (IU/L)
Week 4 | 22 ± 4 | 27 ± 5^b^ | 25 ± 7 | 30 ± 4
Week 16 | 38 ± 4^c^ | 64 ± 9* | 77 ± 8**^c^ | 263 ± 43**^c^
Week 26 | 14 ± 4^b^ | 31 ± 3** | 45 ± 3** | 126 ± 14**
Week 39 | 25 ± 2 | 43 ± 4** | 93 ± 6** | 219 ± 23**
Albumin (g/dL)
Week 4 | 0.01 ± 0.00 | 0.01 ± 0.01 | 0.01 ± 0.01 | 0.00 ± 0.00
Week 16 | 0.02 ± 0.01^c^ | 0.03 ± 0.01 | 0.01 ± 0.00^c^ | 0.02 ± 0.01^c^
Week 26 | 0.02 ± 0.01 | 0.03 ± 0.01 | 0.01 ± 0.00 | 0.02 ± 0.01
Week 39 | 0.02 ± 0.01 | 0.01 ± 0.01 | 0.01 ± 0.01 | 0.02 ± 0.01
Female
n | 8 | 8 | 8 | 8
Viable Cells (%)
Week 4 | 84.15 ± 3.63 | 82.81 ± 4.89 | 88.60 ± 1.84 | 90.39 ± 1.38
Week 26 | 93.45 ± 0.71 | 93.95 ± 1.38 | 94.66 ± 1.67 | 98.43 ± 0.36**
Total Cells Counted
Week 4 | 353.8 ± 32.0 | 337.5 ± 22.4 | 341.3 ± 16.6 | 268.8 ± 20.2
Week 26 | 248.1 ± 22.2 | 288.1 ± 15.2 | 490.0 ± 51.6** | 1,766.9 ± 95.1**
Macrophages (%)
Week 4 | 99.8 ± 0.1 | 99.4 ± 0.1 | 99.8 ± 0.1 | 96.0 ± 1.9*
Week 26 | 99.5 ± 0.2 | 92.2 ± 2.4** | 71.0 ± 2.6** | 30.0 ± 2.0**
Absolute Macrophages (#/µL)
Week 4 | 353.0 ± 31.8 | 335.6 ± 22.3 | 340.7 ± 16.6 | 257.6 ± 19.6*
Week 26 | 246.9 ± 22.1 | 264.1 ± 10.7 | 351.2 ± 42.3* | 525.6 ± 40.0**
Lymphocytes (%)
Week 4 | 0.000 ± 0.000 | 0.338 ± 0.115* | 0.163 ± 0.091 | 0.363 ± 0.158*
Week 26 | 0.038 ± 0.038 | 0.650 ± 0.197* | 1.575 ± 0.184** | 2.088 ± 0.391**
Absolute Lymphocytes (#/µL)
Week 4 | 0.000 ± 0.000 | 0.013 ± 0.339* | 0.588 ± 0.325 | 1.038 ± 0.499
Week 26 | 0.113 ± 0.113 | 1.975 ± 0.641* | 7.638 ± 1.125** | 38.475 ± 9.136**
Neutrophils (%)
Week 4 | 0.213 ± 0.113 | 0.250 ± 0.139 | 0.000 ± 0.000 | 3.650 ± 1.713
Week 26 | 0.450 ± 0.154 | 7.163 ± 2.181** | 27.463 ± 2.634** | 67.950 ± 1.916**
Absolute Neutrophils (#/µL)
Week 4 | 0.800 ± 0.467 | 0.888 ± 0.534 | 0.000 ± 0.000 | 10.138 ± 5.284
Week 26 | 1.163 ± 0.362 | 22.000 ± 7.745** | 131.175 ± 14.546** | 1,202.813 ± 77.715**
Eosinophils (%)
Week 4 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 26 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Absolute Eosinophils (#/µL)
Week 4 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 26 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Lactate Dehydrogenase (IU/L)
Week 4 | 24 ± 2 | 24 ± 2 | 26 ± 4 | 35 ± 5
Week 26 | 14 ± 4 | 29 ± 4* | 71 ± 4** | 212 ± 17**
Albumin (g/dL)
Week 4 | 0.01 ± 0.00 | 0.02 ± 0.01 | 0.03 ± 0.01 | 0.06 ± 0.01**
Week 26 | 0.03 ± 0.01 | 0.05 ± 0.01 | 0.06 ± 0.01 | 0.05 ± 0.01

* Significantly different (p ≤ 0.05) from the chamber control group by Dunn’s or Shirley’s test.

** p ≤ 0.01.

^a^ Data are presented as mean ± standard error.

^b^ n = 7.

^c^ n = 8.

Specular hematite lung burdens rose steadily with time and did not reach steady-state levels; at week 39, lung burdens were approximately 5, 12, and 23 mg specular hematite/g lung in the 15, 30, and 60 mg/m^3^ male rats, respectively (Table B-21). Normalized lung burdens and calculated deposition rates were proportional to exposure concentrations (Table B-21 and Table B-24). The calculated lung deposition rates were 44, 76, and 160 μg specular hematite/total lung per day for the 15, 30, and 60 mg/m^3^ exposure concentrations, respectively (Table B-24). Specular hematite burdens in bronchial lymph nodes were generally greater than those of mediastinal lymph nodes, however, burdens in both types of lymph nodes were quite variable (Table B-22 and Table B-23). Specular hematite lung clearance rates were slow following specular hematite exposures. In the 15 mg/m^3^ group, approximately 0.3% of the daily deposited lung burden was cleared each day and the clearance half-life was estimated to be 212 days (Table B-24). Model-fitting the 30 and 60 mg/m^3^ concentrations resulted in non-meaningful (negative) clearance rates in which 95% confidence intervals each included zero, indicating the calculated clearance rates were indistinguishable from zero. Actual clearance rates for these exposure groups were likely relatively small in magnitude. By week 39, the lung specular hematite volumes for the 30 and 60 mg/m^3^ groups exceeded the overload threshold by factors of 2.3 and 5.5, respectively; overload began in these groups at 118 and 55 days, respectively (Table B-25). For the 15 mg/m^3^ group at week 39, specular hematite volume was 90% of the overload threshold and overload was estimated to begin at 344 days (Table B-25). Tissue burdens of specular hematite, although quite large, were proportional to exposure concentration in the lungs but were quite variable in the lymph nodes. The large lung burdens, the very small clearance rates (indistinguishable from zero in some groups), and the magnitude by which 6% of the alveolar macrophage lung volume was exceeded (or nearly exceeded) by the end of the study, indicated that lung overload conditions were achieved for specular hematite at all exposure concentrations tested in this study.

Lung burden modeling in both the blasting sand and specular hematite studies demonstrated very small (in some cases indistinguishable from zero) clearance rates that resulted in corresponding clearance half-lives that were much longer than those predicted from the respective 2-week studies. Because the density of blasting sand is less than that of specular hematite, lung overload was calculated (by volume) to begin much earlier for all blasting sand exposure groups.

Test article-related gross lesions at necropsy included enlarged and mottled lymph nodes. Test article-related nonneoplastic lesions occurred in the lung, larynx, nose, trachea, and bronchial and mediastinal lymph nodes (Table 13). One 30 mg/m^3^ male rat had an alveolar/bronchiolar adenoma at the 26-week interim evaluation.

Table 13 Incidences of Selected Nonneoplastic Lesions in Male Sprague Dawley Rats in the 39-week Inhalation Study of Specular Hematite

| Chamber Control | 15 mg/m^3^ | 30 mg/m^3^ | 60 mg/m^3^
Four-week Interim Evaluation
Larynx^a^ | 8 | 8 | 8 | 8
Epiglottis, metaplasia, squamous^b^ | 0 | 1 (1.0)^c^ | 4* (1.0) | 5* (1.0)
Foreign body material | 0 | 7** | 8** | 8**
Lung | 8 | 8 | 8 | 8
Infiltration cellular, histiocyte | 1 (1.0) | 1 (1.0) | 1 (1.0) | 8** (1.0)
Foreign body material | 0 | 8** | 8** | 8**
Lymph Node, Bronchial | 8 | 8 | 7 | 8
Foreign body material | 0 | 0 | 2 | 5*
Lymph Node, Mediastinal | 5 | 6 | 6 | 5
Foreign body material | 0 | 0 | 0 | 1
16-week Interim Evaluation
Nose | 8 | 8 | 8 | 8
Olfactory epithelium, accumulation, hyaline droplet | 7 (1.1) | 8 (1.1) | 7 (1.1) | 8 (1.0)
Respiratory epithelium, accumulation, hyaline droplet | 1 (1.0) | 4 (1.0) | 5 (1.0) | 2 (1.0)
Larynx | 8 | 8 | 8 | 8
Epiglottis, metaplasia, squamous | 0 | 3 (1.0) | 3 (1.0) | 4* (1.0)
Foreign body material | 0 | 8** | 8** | 8**
Lung | 8 | 8 | 8 | 8
Infiltration cellular, histiocyte | 2 (1.0) | 8** (1.0) | 8** (1.1) | 8** (2.3)
Inflammation, chronic active | 1 (1.0) | 0 | 0 | 3 (1.0)
Alveolar epithelial, hyperplasia | 0 | 3 (1.0) | 8** (1.0) | 8** (1.0)
Foreign body material | 0 | 8** | 8** | 8**
Lymph Node, Bronchial | 8 | 7 | 8 | 8
Foreign body | 0 | 7** | 6** | 7**
Infiltration cellular, histiocyte | 0 | 2 (2.0) | 6** (2.3) | 7** (2.7)
Hyperplasia | 0 | 1 (2.0) | 2 (1.5) | 3 (1.7)
Lymph Node, Mediastinal | 6 | 8 | 8 | 8
Foreign body material | 0 | 4 | 6** | 8**
Infiltration cellular, histiocyte | 0 | 3 (2.0) | 5* (2.6) | 8** (2.9)
Hyperplasia | 0 | 3 (2.0) | 6** (2.5) | 8** (2.6)
26-week Interim Evaluation
Nose | 8 | 8 | 8 | 8
Olfactory epithelium, accumulation, hyaline droplet | 8 (1.3) | 8 (1.8) | 8 (1.3) | 8 (1.9)
Respiratory epithelium, accumulation, hyaline droplet | 2 (1.0) | 2 (1.0) | 3 (1.0) | 5 (1.0)
Larynx | 8 | 8 | 8 | 8
Epiglottis, metaplasia, squamous | 0 | 5* (1.0) | 5* (1.0) | 7** (1.0)
Foreign body material | 0 | 8** | 8** | 8**
Trachea | 8 | 8 | 8 | 8
Foreign body material | 0 | 1 | 3 | 1
Lung | 8 | 8 | 8 | 8
Infiltration cellular, histiocyte | 2 (1.0) | 8** (1.0) | 8** (1.5) | 8** (2.6)
Inflammation, chronic active | 0 | 2 (1.0) | 0 | 4* (1.0)
Interstitium, fibrosis | 0 | 0 | 0 | 3 (1.3)
Alveolar epithelial, hyperplasia | 0 | 8** (1.0) | 8** (1.0) | 8** (2.0)
Foreign body material | 0 | 8** | 8** | 8**
Lymph Node, Bronchial | 7 | 5 | 7 | 7
Foreign body material | 0 | 5** | 7** | 5**
Infiltration cellular, histiocyte | 0 | 3* (2.3) | 7** (2.7) | 5** (2.8)
Lymph Node, Mediastinal | 8 | 7 | 8 | 8
Foreign body material | 0 | 6** | 7** | 7**
Infiltration cellular, histiocyte | 0 | 5** (2.4) | 7** (2.6) | 7** (2.9)
Hyperplasia | 0 | 3 (1.0) | 3 (1.0) | 6** (2.5)
39-week Evaluation
Nose | 9 | 8 | 8 | 9
Olfactory epithelium, accumulation, hyaline droplet | 8 (2.1) | 8 (2.8) | 8 (3.0) | 8 (3.5)
Larynx | 9 | 8 | 8 | 9
Epiglottis, metaplasia, squamous | 0 | 5** (1.0) | 7** (1.0) | 7** (1.0)
Foreign body material | 0 | 8** | 8** | 9**
Lung | 9 | 8 | 8 | 9
Infiltration cellular, histiocyte | 4 (1.0) | 8* (1.4) | 8* (2.0) | 8 (3.0)
Inflammation, chronic active | 0 | 3 (1.0) | 2 (1.0) | 7** (1.4)
Interstitium, fibrosis | 1 (1.0) | 2 (1.0) | 8** (1.0) | 9** (2.0)
Alveolar epithelial, hyperplasia | 2 (1.5) | 8** (1.0) | 8** (1.0) | 9** (2.0)
Foreign body material | 0 | 8** | 8** | 9**
Lymph Node, Bronchial | 5 | 7 | 8 | 8
Foreign body material | 0 | 5* | 7** | 7**
Infiltration cellular, histiocyte | 0 | 5* (2.4) | 7** (2.7) | 7** (3.0)
Hyperplasia | 0 | 1 (1.0) | 3 (1.3) | 4 (1.3)
Lymph Node, Mediastinal | 9 | 8 | 7 | 9
Foreign body material | 0 | 7** | 6** | 9**
Infiltration cellular, histiocyte | 0 | 7** (2.6) | 6** (3.0) | 9** (3.0)
Hyperplasia | 0 | 3 (1.7) | 4* (1.8) | 7** (3.0)

* Significantly different (p ≤ 0.05) from the chamber control group by the Fisher exact test.

** p ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Exposure-related lesions in the lung included histiocytic cellular infiltration, chronic active inflammation, interstitial fibrosis, alveolar epithelial hyperplasia, and foreign bodies (presumably the test article) (Table 13). As with blasting sand, the majority of these lesions were graded according to the following scale: minimal: ≤5%; mild: greater than 5% but ≤35%; moderate: greater than 35% but ≤65%; and marked: greater than 65% of alveoli affected. Alveolar epithelial hyperplasia was considered minimal when less than 10% of alveolar spaces were lined by hyperplastic pneumocytes, and mild when 10–30% of alveolar spaces were lined by hyperplastic pneumocytes.

Compared to the incidence in the chamber control group, significant increases in the incidence of histiocytic cellular infiltration occurred in all exposed groups at weeks 16 and 26, in the 60 mg/m^3^ group at week 4, and in the 15 and 30 mg/m^3^ groups at 39 weeks (Table 13). Except at 4 weeks, the severity of this lesion increased with increasing exposure concentration. The incidence of chronic active inflammation was significantly increased in the 60 mg/m^3^ group at weeks 26 and 39, and the severity of this lesion was slightly increased in this group at 39 weeks. Histiocytic cellular infiltration was characterized by increased numbers of alveolar macrophages.

Many of the macrophages, particularly at higher exposure concentrations, contained fine intracytoplasmic foreign bodies (granular material), presumed to be test material. Chronic active inflammation was diagnosed when the increased numbers of macrophages were accompanied by scattered neutrophils and/or lymphocytes. With longer exposure duration and greater exposure concentrations, the alveolar septa were often thickened by mononuclear inflammatory cells, fibrosis, and alveolar epithelial hyperplasia.

The incidence of minimal to mild interstitial fibrosis in the 30 and 60 mg/m^3^ groups at 39 weeks was significantly greater than that in the chamber control group, and the severity was increased in the 60 mg/m^3^ group (Table 13). Fibrosis was typically seen in areas also affected by chronic active inflammation, histiocytic cellular infiltration, or alveolar epithelial hyperplasia. Interstitial fibrosis was characterized by an increase in lacey-collagen fibers in the alveolar septa.

The incidence of alveolar epithelial hyperplasia was significantly increased in the 30 and 60 mg/m^3^ groups at week 16 and in all exposed groups at weeks 26 and 39, compared to the chamber control group incidence (Table 13). The lesions were associated with chronic active inflammation, and they were indicative of a regenerative response of alveolar epithelial cells. Alveolar epithelial hyperplasia was characterized by cuboidal cells lining the alveolar septa in areas with inflammation. The cuboidal cells were closely packed with severe inflammation and sparsely distributed with less severe inflammation. The lesion did not cause compression of adjacent tissue.

Foreign body accumulation was noted in the lungs of all exposed rats at all time points and in none of the chamber control rats (Table 13). The lesion was characterized by fine, dark brown to black granular material within the cytoplasm of alveolar macrophages or free within the alveolar spaces. The number of macrophages containing the material increased with increasing exposure concentration. The absence of the material in the lungs of chamber control rats, the correlation between exposure concentration and the amount of the material, and the morphology of the material are consistent with specular hematite.

In the larynx, exposure-related lesions included squamous metaplasia of the epiglottis and foreign body material (Table 13). The incidence of minimal squamous metaplasia of the epithelium at the base of the epiglottis was significantly increased in the 60 mg/m^3^ group at all time points, in the 30 mg/m^3^ group at weeks 4, 26, and 39, and in the 15 mg/m^3^ group at weeks 26 and 39. Squamous metaplasia was characterized by replacement of the normally cuboidal epithelium by flattened and elongated epithelial cells. Foreign body accumulation occurred in all exposed male rats at all time points except at 4 weeks in the 15 mg/m^3^ group; foreign body material did not occur in any of the chamber control rats. Morphologically, foreign body material in the larynx was identical to that seen in the lung and was characterized by fine, dark brown to black granular material. The material was present in the cytoplasm of epithelial cells or extracellularly, or in the cytoplasm of macrophages in the mucosa, submucosa, or on the luminal surface at the base of the epiglottis. As in the lung, the morphological appearance and association with exposure were consistent with the material being specular hematite. Two rats, one in the 15 mg/m^3^ group at 26 weeks and one in the 60 mg/m^3^ group at 39 weeks, had minimal or mild ulceration of the laryngeal epithelium. It was unclear whether this lesion was related to exposure to specular hematite.

In the nose, accumulation of hyaline droplets in the olfactory epithelium occurred in most male rats, including chamber control animals beginning at week 16; the severity of the lesion generally increased with increasing exposure concentration at 39 weeks (Table 13). Hyaline droplet accumulation in the respiratory epithelium also occurred beginning at week 16; although the incidence in the exposed groups was greater than those in the chamber control group, the differences were not statistically significant. Hyaline droplets are normally seen in control animals but may be increased in size and have a greater distribution with exposure to various chemicals or particulates in inhalation studies. Hyaline droplet accumulation in the olfactory and respiratory epithelia was noted primarily at Levels II and III of the nose and consisted of brightly eosinophilic intracytoplasmic globules that occasionally distorted cells and displaced nuclei. Locations commonly affected were the septum and medial nasoturbinates at the junction of the respiratory and olfactory epithelium in Level II and the olfactory epithelium in the ventral half of Level III.

In the trachea, foreign body accumulation occurred in all exposed groups and chronic active inflammation occurred in all groups at 26 weeks; differences from the chamber control group incidence were not significant (Table 13). Foreign body material was characterized by small amounts of dark brown to black, finely granular material present in the cytoplasm of epithelial cells, or extracellularly, or in the cytoplasm of macrophages in the mucosa, submucosa, or on the luminal surface of the trachea. As in the lung and larynx, the morphological appearance and association with exposure were consistent with the material being specular hematite.

Exposure-related increases in the incidences of foreign bodies, histiocytic cellular infiltration, and hyperplasia occurred in the bronchial and mediastinal lymph nodes (Table 13). The presence of foreign body material in the bronchial lymph nodes was significantly increased in the 60 mg/m^3^ group beginning at week 4 and in the 15 and 30 mg/m^3^ groups beginning at week 16, compared to the chamber control group incidence. The presence of foreign body material in the mediastinal lymph node was significantly increased beginning at week 16 in the 30 and 60 mg/m^3^ groups and beginning at week 26 in the 15 mg/m^3^ group. The morphological appearance of the foreign body material was identical to that in the respiratory system. It was characterized by fine, dark brown to black granular material in the cytoplasm of macrophages.

The incidence of minimal to mild histiocytic cellular infiltration in the bronchial and mediastinal lymph nodes was significantly increased beginning at week 16 in the 30 and 60 mg/m^3^ groups and at week 26 in the 15 mg/m^3^ group (Table 13). The severity of the lesion generally increased with exposure concentration and was most severe at 39 weeks. Histiocyte cellular infiltration was characterized by the presence of excessive numbers or aggregates of macrophages containing intracytoplasmic foreign body material that was presumed to be specular hematite. The macrophages were seen primarily in subcortical, paracortical, and medullary sinuses and were similar in appearance to the foreign body-laden macrophages in the lungs. Often the deposits of foreign bodies were so large that cytoplasmic and nuclear detail were obscured. The histiocytic cellular infiltrates often contributed to the overall enlargement of the nodes, and many nodes were noted as trackable gross lesions due to enlargement or dark red mottling. All the macrophages and foreign body material were presumed to have migrated to the lymph nodes from the lungs.

Hyperplasia occurred in the bronchial and mediastinal lymph nodes in some exposed animals beginning at 16 weeks, and the incidence of hyperplasia in the mediastinal lymph node in 30 and 60 mg/m^3^ rats was generally significantly greater than that of the chamber control group (Table 13). The incidence of hyperplasia was greater in the mediastinal lymph node than in the bronchial lymph node. The severity of this lesion generally increased with time and exposure concentration and was slightly greater in the mediastinal lymph nodes compared to the bronchial lymph nodes. Hyperplasia was characterized by an increase in the number of primarily small and intermediate sized lymphocytes in the paracortex, resulting in increased paracortical area.

## Immunotoxicity Studies

The predominant effect on measures of immunity and inflammation was an exposure concentration-related increase in MCP-1 levels in BAL fluid after exposure to blasting sand and specular hematite. Changes in MCP-1 were the most significant effect; however, data for the other immunotoxicity endpoints that were tested are in Appendix F. Male rats exposed to 60 mg/m^3^ blasting sand for 4 weeks had significantly increased levels of MCP-1 in BAL fluid; MCP-1 levels were significantly increased at all exposure levels of blasting sand at the 16-, 26-, and 39-week evaluations (Table F-14 and Figure 7. Similar increases in MCP-1 levels were observed at 26 weeks in the BAL fluid from female rats exposed to blasting sand (Table F-13). The exposure concentration and duration of exposure to blasting sand appeared to be important factors contributing to the changes in MCP-1 levels. There were no significant alterations in any of the other cytokines or chemokines measured at any of the time points evaluated.

Figure 7

MCP-1 Levels in the Bronchoalveolar Lavage Fluid of Male Sprague Dawley Rats Exposed to Blasting Sand by Inhalation for 4, 16, 26, or 39 Weeks

**Significantly different (p ≤ 0.01) from the chamber control group at the same time point.

^#^Significantly different (p ≤ 0.05) from the week 4 time point within the same exposure concentration.

^##^p ≤ 0.01.

MCP-1 levels were also significantly increased in an exposure concentration-related manner in male rats exposed to specular hematite at doses of 30 or 60 mg/m^3^, beginning at the 16-week time point (Table F-29). Exposure to specular hematite for 26 weeks also resulted in a significant increase in MCP-1 levels in males exposed to 15 mg/m^3^. After 39 weeks of exposure to specular hematite, MCP-1 levels were significantly increased in BAL fluid from the 30 and 60 mg/m^3^ groups (Table F-29 and Figure 8). Similar increases in MCP-1 levels were observed in female rats exposed to 30 or 60 mg/m^3^ at the 26-week time point (Table F-28).

Figure 8

MCP-1 Levels in Bronchoalveolar Lavage Fluid of Male Sprague Dawley Rats Exposed to Specular Hematite by Inhalation for 4, 16, 26, or 39 Weeks

**Significantly different (p ≤ 0.01) from the chamber control group at the same time point.

^#^Significantly different (p ≤ 0.05) from the week 4 time point within the same exposure concentration.

^##^ p ≤ 0.01.

Limited effects were observed on measures of immunity in female rats exposed to either blasting sand or specular hematite (detailed results are provided in Appendix F). No significant effects were observed on the antibody-forming cell (AFC) response, serum anti-sheep red blood cell (sRBC) IgM antibody levels, or natural killer (NK) cell activity in female rats exposed to blasting sand at either the 4-week or 26-week time point. Minimal changes in leukocyte subpopulations in the spleen were observed in female rats exposed to 60 mg/m^3^ blasting sand for 26 weeks. Anti-CD3 mediated spleen cell proliferation was unaffected at 4 weeks but was increased at 26 weeks in rats exposed to 60 mg/m^3^ blasting sand.

No significant effects were observed in any of the immunological assays, including the AFC response, serum IgM antibody levels against sRBCs, spleen cell numbers, spleen cell phenotypes, anti-CD3 mediated proliferation, or NK cell activity following exposure to specular hematite (Appendix F).