# Introduction

## Characteristics of Abrasive Blasting Agents

Blasting sand contains varying levels of crystalline silica (SiO_2_), also known as quartz, which can range widely (39% to 100%) between commercially available samples.^1^ Specular hematite primarily consists of iron oxide (Fe_2_O_3_). Garnet refers to a group of complex silicate materials with isometric crystal structures and similar properties and chemical compositions.^6^ Coal slag is a waste product from the burning of coal in power plants^4,7,8^ and contains very low levels of crystalline silica (less than 1%). Crushed glass is generated from recycled glass and contains no crystalline silica.

## Production, Use, and Human Exposure

Abrasive blasting involves forcefully projecting a stream of abrasive particles onto a surface, typically using compressed air or steam. Because sand (composed primarily of crystalline silica) is commonly used in the abrasive blasting process, workers who perform this work are commonly known as sandblasters. Tasks performed by sandblasters include removing irregularities from foundry castings; cleaning and removing paint from ship hulls, stone buildings, metal bridges, and other metal surfaces; finishing tombstones; etching or frosting glass; and performing certain artistic endeavors. Total use of blasting sand in 1992 was 1.75 million tons.^9^ When workers inhale the crystalline silica from the sand used in abrasive blasting, their lung tissue reacts by developing fibrotic nodules and scarring around the trapped silica particles.^10^ This fibrotic condition of the lung is called silicosis. If the nodules grow too large, breathing becomes difficult and death can result. Silicosis victims are also at high risk of developing active tuberculosis.^11-13^

Coal slag is the most commonly used abrasive blasting alternative to silica sand.^1,9^ It is used in approximately 42% of all blasting operations that use alternative agents. Coal slag is a waste product of burning coal in power plants.^4,7,8^ The slag is formed during the burning of powdered coal, which produces an ash with a relatively low melting point. During the burning process, this molten ash falls to the bottom of the furnace as a viscous liquid before then dropping into water where it solidifies. The resulting solid is distributed under the trademark Black Beauty^®^. Compared with other mineral slags (copper and nickel), coal slags as a class are reported to contain the lowest quantities (μg/g) of suspected carcinogens: beryllium (7 to 48 μg/g), chromium (110 to 200 μg/g), nickel (18 to 70 μg/g), and arsenic (4 to 18 μg/g).^8^ Crushed glass is a relatively new abrasive blasting agent used in shipbuilding and repair with projected annual usage of 2,725 tons.^4^ As crushed glass contains no free crystalline silica, it is considered a potentially safer alternative blasting material.^4,5^ In addition, the vast supply of recycled glass could be a favorable economic factor in considering the increased use of crushed glass. In 2004, abrasive blasting accounted for 35% of the estimated 58,600 tons of garnet consumed in the United States.^6^ Recent annual consumption of specular hematite was estimated to be about 25,000 to 30,000 tons.^14^

NIOSH estimates that approximately 150,000 workers are employed as abrasive blasters.^15^ The National Occupational Exposure Survey indicates that the construction industry employs the largest number of sandblasters, with the highest proportion in the special trades industries.^3,16,17^ Silica sand constitutes approximately 63% of all blasting abrasives used industrially. Overexposure to crystalline silica and silicosis are still prevalent among sandblasters^18^ (unpublished SENSOR data). For many abrasive blasting operations, nearby workers (pot tenders, blaster helpers, shipyard workers, painters, welders, and laborers) are without any respiratory protection, so the total number of workers exposed to abrasive blasting materials is likely a multiple of the estimated number of sandblasters.

## Regulatory Status

The current Occupational Safety and Health Administration (OSHA) permissible exposure limit (PEL) for respirable crystalline silica is 100 μg/m^3^ as an 8-hour time-weighted average.^19^ The NIOSH recommended exposure limit (REL) for respirable crystalline silica is 50 μg/m^3^ as a time-weighted average for up to 10 hours per day during a 40-hour work week.^2^ This REL is intended to prevent silicosis. However, evidence indicates that crystalline silica is a potential occupational carcinogen^16,20,21^ and NIOSH is reviewing the data on carcinogenicity. NIOSH, OSHA, and the American Conference of Governmental Industrial Hygienists (ACGIH) do not have specific RELs, PELs, or threshold limit values (TLVs) for any abrasive blasting alternatives to silica sand. These substitutes are currently treated as nuisance dusts with exposure limits of 3 mg/m^3^ (respirable particles) and 10 mg/m^3^ (inhalable particles) according to ACGIH.^22^ Specular hematite primarily consists of iron oxide; the NIOSH REL and ACGIH TLV for iron oxide dust and fumes is 5 mg/m^3^, and the OSHA PEL is 10 mg/m^3^.

Acute silicosis is less common today than it was in the 1930s because engineering controls are available to reduce exposure to respirable crystalline silica and the use of alternative abrasives is increasing. However, data indicate that many abrasive blasters continue to work without adequate respiratory protection,^23^ and ventilation controls for reducing crystalline silica exposures are not used in most industries.^17^ Samimi et al.^24^ found that, even in short-term sandblasting operations (less than 2.5 hours of blasting during an 8-hour work day), the average concentration of dust was 764 μg/m^3^, with an average crystalline silica content of 25.5%. This average crystalline silica concentration was twice the 1974 OSHA standard. In a 1974 study of respiratory protection practices during abrasive blasting,^23^ the protection factors for supplied-air respirators with helmets ranged from 1.9 to 3,750. This wide range was attributed to the varied conditions of the equipment rather than to the superiority of any brand. Maintenance was universally poor or nonexistent, and those responsible for selecting respiratory protection for abrasive blasting were inadequately informed about the proper use and maintenance of the equipment. The higher protection factors were associated with high rates of helmet air flow, but these high flow rates increased noise levels due to air turbulence. The study also indicated that the blasters’ helmets tended to fall from their shoulders when they stooped.

Because of the high risk for silicosis in sandblasters and the difficulty in controlling exposures, the use of crystalline silica for blast cleaning operations was restricted in Great Britain in 1950^25^ and in other European countries in 1966.^26^ In 1974, NIOSH recommended silica sand (or other substances containing more than 1% crystalline silica) be prohibited as an abrasive blasting material and less hazardous materials be used in blasting operations,^2^ due to the silicosis hazard and the difficulty controlling crystalline silica exposure associated with sandblasting. Alternatives to silica sand are recommended by NIOSH^3^; however, few comprehensive studies have been conducted to evaluate the health effects of most of the alternative blasting abrasives.

A variety of materials (coal and other slags, crushed glass, garnet, specular hematite olivine, staurolite, and steel grit) are available as alternative blasting media.^23,27,28^ Engineering controls and personal protective equipment should be used with any of the alternative abrasives to reduce inherent hazards associated with use of blasting abrasives and substrates. In addition to the health hazards of abrasive blasting materials, the finely fractured particles of material being removed (lead paint, for example) likely pose other health risks for workers.^29^

## Toxicity

### Experimental Animals

#### Crystalline Silica

Studies show that exposure of animals to crystalline silica by inhalation, oropharyngeal aspiration, or intratracheal instillation causes lung injury, inflammation, and pulmonary fibrosis. Other evidence suggests that the crystalline silica content of blasting sand correlates with pulmonary toxicity.^1^

#### Coal Slag

In studies conducted by MacKay et al.,^27^ male rats received single intralobular instillations of distilled water (control), coal slag (20 mg), or quartz (20 mg). All surviving rats were sacrificed 10 months later. Microscopic evaluation of the lungs indicated mean fibrotic scores of 4 for the coal slag lungs compared with 10 for the quartz-treated group. Stettler et al.^7^ dosed male Sprague Dawley rats with single intratracheal instillations of 40 mg coal slag, 40 mg quartz, or vehicle. Interim sacrifices were conducted at 2 days, 3 months, and 6 months, with a terminal sacrifice at 12 months. Mild to moderate interstitial fibrosis that progressed with time was noted in each of the coal slag-exposed rats. Histiocytic infiltrates containing particulate material were seen in tracheobronchial lymph nodes and increased with time; fibrosis was a prominent feature at 12 months. These changes were much less severe than those resulting from exposure to quartz. Massive fibrosis and inflammation developed in much of the entire lobe of the lungs at 3, 6, and 12 months in the quartz group, but these lesions were not evident at any time in any animal in the coal slag groups. Pulmonary function data for the coal slag groups showed less adverse lung effects for coal slag compared with quartz exposure, generally falling between the silica quartz and the vehicle control groups in terms of impact to lung function at both doses and elevated neutrophil levels at the 10 mg level. In addition, these parameters exceeded those in the quartz-dosed group. Lung hydroxyproline levels were significantly elevated only in rats receiving 10 mg of coal slag. By contrast, histopathological fibrosis scores, based on severity and distribution, were significantly higher than vehicle controls only in the rats receiving 10 mg of quartz.

#### Crushed Glass

In a study by Porter et al.,^5^ male Sprague Dawley rats were dosed by intratracheal instillation with 10 mg per rat of respirable vehicle, crushed glass, or blasting sand (silica quartz). Bronchoalveolar lavage fluid was evaluated 4 weeks later for pulmonary inflammation (including neutrophil counts) and damage (serum albumin concentration and lactate dehydrogenase activity). Lungs were evaluated microscopically for fibrosis, alveolitis, and alveolar hypertrophy and hyperplasia. The results from this study showed that crushed glass significantly increased polymorphonuclear neutrophil yields and lactate dehydrogenase activity in bronchoalveolar lavage fluid above vehicle control levels to levels comparable to those seen following silica quartz treatment. Bronchoalveolar lavage fluid albumin levels were comparable to vehicle controls and significantly lower than levels noted with silica quartz treatment. Histopathology scores (severity and distribution) of microscopic changes (fibrosis, alveolitis, and alveolar hypertrophy and hyperplasia) were all significantly greater than those of the vehicle control group and comparable to those of silica quartz group.

#### Garnet

Studies examining the toxicological effects of garnet exposures are limited. In the study by Hubbs et al.,^1^ male Sprague Dawley rats were dosed with garnet via a single intratracheal instillation (2.5 or 10 mg/rat) and necropsied 4 weeks later. In garnet-dosed rats, significant treatment-related responses were restricted to the 10 mg group. Toxicity due to garnet treatment included increased lactate dehydrogenase activity, and increased neutrophil and activated macrophage counts in lung bronchoalveolar lavage fluid. These results suggested that garnet caused pulmonary cytotoxicity and inflammation that persisted for 4 weeks after exposure.

#### Specular Hematite

Specular hematite appears to exhibit low toxicity in vivo compared with crystalline silica. In one study, intratracheal instillation of 10 mg crystalline silica per hamster resulted in recruitment of polymorphonuclear leukocytes and elevation of red blood cell counts, lactate dehydrogenase activity, and albumin levels in lavage fluid, which were significant 1 day postexposure.^30^ By contrast, Beck and colleagues found in a separate study that specular hematite caused much less inflammation and damage than crystalline silica, and these pulmonary reactions were quickly resolved. The results agree with those of a NIOSH study^1^ that examined rats 30 days after intratracheal instillation of 10 mg specular hematite per rat; bronchoalveolar lavage markers of inflammation and damage were not significantly different from vehicle control levels and were significantly lower than marker values observed after blasting sand (crystalline silica) instillation. Histopathologically, the incidence of lung fibrosis was also lower following exposure to specular hematite compared with levels from blasting sand exposure. Mild, transient inflammation has also been reported after short-term (3 hours) inhalation of high levels (274 mg/m^3^) of specular hematite by hamsters.^31^ Specular hematite, in contrast to crystalline silica, failed to induce significant secretion of inflammatory cytokines (tumor necrosis factor alpha and interleukin 1) in rat lungs after intratracheal exposure.^32^ The lack of sustained inflammation and lung damage after exposure of animal models to iron oxide is consistent with the absence of pulmonary fibrosis reported in rats after intratracheal instillation of specular hematite.^1,33^ In summary, the in vivo animal data for lung fibrosis from exposure to specular hematite consistently indicated fewer adverse effects from exposure to iron oxide than to crystalline silica.

### Humans

#### Crystalline Silica

A 1980 Department of Labor report to Congress on occupational disease estimated that one million workers were exposed to crystalline silica. Regardless of the use of respiratory protection, sporadic clusters of silicosis continue to occur in the sandblasting industry.^30,31^ Overexposures to crystalline silica and silicosis are still prevalent among abrasive blasting workers^18^(unpublished SENSOR data). Blasting with silica is restricted in several other industrialized nations, but it continues to be widely practiced in the United States despite the recommendation by NIOSH to ban it.^23^

When workers inhale the crystalline silica used in abrasive blasting, the lung tissue can react by developing either acute or chronic silicosis, depending on the exposure level. Acute silicosis is characterized by alveolar lipoproteinosis and a decrease in gas exchange. Chronic silicosis is characterized by fibrotic nodules and scarring around the trapped silica particles.^10^ If the nodules grow too large, breathing becomes difficult and death can result. Silicosis victims are also at high risk for developing active tuberculosis.^11-13^ The silica sand used in abrasive blasting typically fractures into fine particles and becomes airborne. Inhalation of freshly fractured silica appears to produce a more severe lung reaction than aged silica that is not freshly fractured.^34-36^ This factor might contribute to the development of acute and accelerated forms of silicosis among sandblasters.

Chronic exposure to low concentrations of crystalline silica promotes the formation of fibrotic nodules in the lung parenchyma with a typical morphological appearance of discrete, rounded, whorled, hyalinized lesions.^37^ These fibrotic nodules are usually less than a centimeter in diameter and are sharply demarcated from the surrounding lung tissue. This simple silicosis rarely results in any clinically apparent disease. With continued exposure, simple silicosis will lead to increased nodular density and decremental changes in pulmonary function. Progressive massive fibrosis is a common feature of such complicated silicosis resulting in compromised lung function.

Acute silicosis is associated with alveolar lipoproteinosis caused by highly reactive fractured silica and/or intense silica dust exposure and is associated with a high mortality rate. Acute silicosis is known to result from sandblasting, silica flour mill operations, rock drilling, tunneling, and other occupations in which crystalline silica is fractured then inhaled.^38,39^ Clinically, it is characterized by severe shortness of breath and hypoxemia. Secondary infection is a common terminal complication. Accelerated silicosis with lipoproteinosis is linked to sandblasting and other aforementioned similar operations.^31,40^ Accelerated silicosis progresses rapidly to classic nodular silicosis at an accelerated rate of 5 to 10 years with no abnormalities except increasing breathlessness. The patient often dies from respiratory failure within 7 to 12 years of diagnosis.

#### Specular Hematite

The relatively low lung fibrogenicity rates from iron oxide exposure in animal studies are consistent with epidemiology studies of exposed workers. For example, Teculescu and Albu^41^ studied 14 workers exposed for an average of 10 years to pure iron oxide dust and found no pulmonary function changes consistent with pulmonary fibrosis. Furthermore, Lay et al.^42^ reported that the presence of inflammation following intrapulmonary instillation of iron oxide in human subjects resolved rapidly after the exposure ended.

## Carcinogenicity

### Experimental Animals

#### Crystalline Silica

Exposure to crystalline silica has been shown to be carcinogenic to the lungs of rats but not those of mice and hamsters^43^; however, rats are relatively more sensitive to the development of lung tumors.^21,44^ Therefore, the biological unresponsiveness of some animal species or strains to a test article does not necessarily negate evidence of carcinogenicity.

#### Specular Hematite

Animal investigations of the carcinogenicity of specular hematite have been consistently negative. Intratracheal instillation (380 mg iron oxide by multiple injections) resulted in no lung tumors in a 2.5-year study with rats.^40^ Similar results were reported by Saffiotti et al.^38^ after 15 weekly instillations of 3 mg iron oxide. Inhalation of iron oxide (40 mg/m^3^ for 2 years) also produced negative results in hamsters.^39^ With this evidence, the International Agency for Research on Cancer (IARC)^45^ views the lack of carcinogenicity in animals from iron oxide exposure as convincing.

There are no carcinogenicity data from animal studies for coal slag, crushed glass, or garnet exposures.

### Humans

#### Crystalline Silica

IARC comprehensively reviewed the human and animal experimental studies and concluded that there is sufficient evidence for the carcinogenicity of inhaled crystalline silica in the forms of quartz or cristobalite from occupational sources.^21,44,46^ IARC classified crystalline silica under category 1A (i.e., a carcinogen to humans).^21,44^ However, the conclusions from human epidemiological studies are debatable, mainly because of the lack of well-matched control studies for smoking and other variables known to be carcinogens. A supporting quantitative relationship between crystalline silica exposure and bronchogenic cancer was also demonstrated in workers without radon exposure such as Vermont granite workers, German slate workers, North Carolina Dusty Trade Workers, and ceramic and pottery workers in Sweden and Italy. Although information is not available for people with silicosis who have never smoked, it can be concluded from these studies that silicosis is correlated with an increased risk for bronchogenic carcinoma. NTP^47^ lists respirable crystalline silica as a Known Human Carcinogen in its 14th Report on Carcinogens.

#### Specular Hematite

Early epidemiology studies reported an increased incidence of lung cancer in workers exposed to iron oxide. However, most of these studies are plagued with confounding exposures.^48^ For example, Boyd et al.^49^ reported a 70% higher than normal lung cancer mortality in underground iron ore miners, whereas surface iron mine workers did not exhibit higher lung cancer mortality. Unaccounted for in this study was the fact that the underground miners were also exposed to high radon levels (100 pCi/L), which could affect lung cancer rates. In addition, a case-control study of factory workers exposed to high amounts of iron oxide dust found no increased incidence of cancer in the respiratory system or other sites.^37^ Therefore, the human data for iron oxide-induced cancer is viewed as negative.^48^ In summary, lung cancer data are consistently negative for in vivo animal exposure studies of specular hematite, and when confounding exposures are accounted for, human data are consistent with this conclusion.

There are no carcinogenicity data from human epidemiological studies for coal slag, crushed glass, or garnet exposures.

## Study Rationale

Acute and chronic inhalation toxicity testing data are needed due to the high production volume of these abrasive blasting compounds, the number of workers exposed, and the inadequacy of available toxicity data to inform safe exposure levels. Because potential alternatives have not been adequately evaluated using comparative methods, making explicit recommendations for less hazardous blasting agent alternatives to silica sand is difficult.^1^ Data generated from inhalation toxicity studies could provide a framework for NIOSH to use in recommending alternative blasting agents to crystalline silica and could provide dose-response toxicity data to recommend occupational exposure limits. Furthermore, an immunotoxicity study was called for to examine the effects of abrasive blasting agents on pulmonary and systemic immune function because of the evidence of a close association between silica exposure and autoimmunity in humans, the reported immunological effects of silicosis in animal models, and systemic effects in animals exposed to particulates.