# Appendix G Supplemental Files

The following supplemental files are available at https://doi.org/10.22427/NTP-DATA-TOX-91.

## G.1 Two-week Blasting Sand Study Tables – Rats

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Site (Systemic Lesions Abridged)

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P14 – Individual Animal Pathology Data

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P40 – Survival Curves

## G.2 Two-week Blasting Sand Individual Animal Data – Rats

Male Individual Animal Body Weight Data

Male Individual Animal Non-Neoplastic Pathology Data

Male Individual Animal Survival Data

Male Individual Animal Terminal Body Weight Data

## G.3 Two-week Coal Slag Study Tables – Rats

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E05 – Clinical Observations Summary

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Site (Systemic Lesions Abridged)

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P14 – Individual Animal Pathology Data

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P40 – Survival Curves

## G.4 Two-week Coal Slag Individual Animal Data – Rats

Male Individual Animal Body Weight Data

Male Individual Animal Non-Neoplastic Pathology Data

Male Individual Animal Survival Data

Male Individual Animal Terminal Body Weight Data

Male Individual Clinical Observations

## G.5 Two-week Crushed Glass Study Tables – Rats

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Site (Systemic Lesions Abridged)

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P14 – Individual Animal Pathology Data

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P40 – Survival Curves

## G.6 Two-week Crushed Glass Individual Animal Data – Rats

Male Individual Animal Body Weight Data

Male Individual Animal Non-Neoplastic Pathology Data

Male Individual Animal Survival Data

Male Individual Animal Terminal Body Weight Data

## G.7 Two-week Garnet Study Tables – Rats

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Site (Systemic Lesions Abridged)

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P14 – Individual Animal Pathology Data

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P40 – Survival Curves

## G.8 Two-week Garnet Individual Animal Data – Rats

Male Individual Animal Body Weight Data

Male Individual Animal Non-Neoplastic Pathology Data

Male Individual Animal Survival Data

Male Individual Animal Terminal Body Weight Data

## G.9 Two-week Specular Hematite Study Tables – Rats

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Site (Systemic Lesions Abridged)

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P14 – Individual Animal Pathology Data

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P40 – Survival Curves

## G.10 Two-week Specular Hematite Individual Animal Data – Rats

Male Individual Animal Body Weight Data

Male Individual Animal Non-Neoplastic Pathology Data

Male Individual Animal Survival Data

Male Individual Animal Terminal Body Weight Data

## G.11 Interim of 39-week Blasting Sand Study at 4 Weeks – Rats

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Sites (Systemic Lesions Abridged)

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

## G.12 Interim of 39-week Blasting Sand Study at 16 Weeks – Rats

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Sites (Systemic Lesions Abridged)

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

## G.13 Interim of 39-week Blasting Sand Study at 26 Weeks – Rats

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Sites (Systemic Lesions Abridged)

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

## G.14 Thirty-nine-week Blasting Sand Study Tables – Rats

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E05 – Clinical Observations Summary

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Sites (Systemic Lesions Abridged)

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P14 – Individual Animal Pathology Data

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P40 – Survival Curves

## G.15 Thirty-nine-week Blasting Sand Individual Animal Data – Rats

Male Individual Animal Body Weight Data

Male Individual Animal Clinical Observations

Male Individual Animal Neoplastic Pathology Data

Male Individual Animal Non-Neoplastic Pathology Data

Male Individual Animal Organ Weight Data

Male Individual Animal Survival Data

## G.16 Interim of 39-week Specular Hematite Study at 4 Weeks – Rats

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Sites (Systemic Lesions Abridged)

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

## G.17 Interim of 39-week Specular Hematite Study at 16 Weeks – Rats

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Sites (Systemic Lesions Abridged)

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

## G.18 Interim of 39-week Specular Hematite Study at 26 Weeks – Rats

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Sites (Systemic Lesions Abridged)

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

## G.19 Thirty-nine-week Specular Hematite Study Tables – Rats

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E05 – Clinical Observations Summary

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Sites (Systemic Lesions Abridged)

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P14 – Individual Animal Pathology Data

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P40 – Survival Curves

## G.20 Thirty-nine-week Specular Hematite Individual Animal Data – Rats

Male Individual Animal Body Weight Data

Male Individual Animal Clinical Observations

Male Individual Animal Neoplastic Pathology Data

Male Individual Animal Non-Neoplastic Pathology Data

Male Individual Animal Organ Weight Data

Male Individual Animal Survival Data