# Appendix E Sentinel Animal Program

## E.1 Methods

Rodents used in the National Toxicology Program are produced in optimally clean facilities to eliminate potential pathogens that may affect study results. The Sentinel Animal Program is part of the periodic monitoring of animal health that occurs during the toxicological evaluation of test compounds. Under this program, the disease state of the rodents is monitored via sera or feces from extra (sentinel) or dosed animals in the study rooms. The sentinel animals and the study animals are subject to identical environmental conditions. Furthermore, the sentinel animals come from the same production source and weanling groups as the animals used for the studies of test compounds.

For these toxicity studies, blood samples were collected from each animal and allowed to clot, and the serum was separated. Additionally, fecal samples were collected and tested for Helicobacter species. All samples were processed appropriately and evaluated for the presence of pathogens. Samples were tested in-house or sent to Research Animal Diagnostic Laboratory (Columbia, MO). The laboratory methods and agents for which testing was performed are tabulated below; the times at which samples were collected during the studies are also listed.

Blood was collected at the following time points during the 39-week studies:

- Week 3; 5 male and five female extra rats
- Week 16; 5 male control rats
- Week 26; 5 female control rats
- Week 39; 5 male control rats

Table E-1 Blasting Sand

Method and Test | Time of Collection
Multiplex Fluorescent Immunoassay
Kilham’s Rat Virus (KRV) | 16, 26, and 39 weeks
Mycoplasma pulmonis | 3, 16, 26, and 39 weeks
Parvo NS-1 | 16, 26, and 39 weeks
Pneumonia Virus of Mice (PVM) | 3, 16, 26, and 39 weeks
Rat Coronavirus/Sialodacryoadenitis Virus (RCV/SDA) | 3, 16, 26, and 39 weeks
Rat Minute Virus (RMV) | 16, 26, and 39 weeks
Rat Parvovirus (RPV) | 3, 16, 26, and 39 weeks
Rat Theilovirus (RTV) | 16, 26, and 39 weeks
Sendai | 3, 16, 26, and 39 weeks
Theiler’s Murine Encephalomyelitis Virus-Mouse Poliovirus, Strain GDVII (TMEV GDVII) | 16, 26, and 39 weeks
Toolan’s H-1 | 16, 26, and 39 weeks

Table E-2 Specular Hematite

Method and Test | Time of Collection
Multiplex Fluorescent Immunoassay
KRV | 3, 16, 26, and 39 weeks
M. pulmonis | 3, 16, 26, and 39 weeks
PVM | 3, 16, 26, and 39 weeks
RCV/SDA | 3, 16, 26, and 39 weeks
RMV | 3, 16, 26, and 39 weeks
RPV | 3, 16, 26, and 39 weeks
RTV | 3, 16, 26, and 39 weeks
Sendai | 3, 16, 26, and 39 weeks
TMEV GDVII | 3, 16, 26, and 39 weeks
Toolan’s H-1 | 3, 16, 26, and 39 weeks

## E.2 Results

All test results were negative.