# Appendix D Ingredients, Nutrient Composition, and Contaminant Levels in NTP-2000 Rat and Mouse Ration

Table D-1 Ingredients of NTP-2000 Rat and Mouse Ration

Ingredients | Percentage by Weight
Ground Hard Winter Wheat | 22.26
Ground #2 Yellow Shelled Corn | 22.18
Wheat Middlings | 15.0
Oat Hulls | 8.5
Alfalfa Meal (Dehydrated, 17% Protein) | 7.5
Purified Cellulose | 5.5
Soybean Meal (49% Protein) | 5.0
Fish Meal (60% Protein) | 4.0
Corn Oil (without Preservatives) | 3.0
Soy Oil (without Preservatives) | 3.0
Dried Brewer’s Yeast | 1.0
Calcium Carbonate (USP) | 0.9
Vitamin Premix^a^ | 0.5
Mineral Premix^b^ | 0.5
Calcium Phosphate, Dibasic (USP) | 0.4
Sodium Chloride | 0.3
Choline Chloride (70% Choline) | 0.26
Methionine | 0.2

USP = United States Pharmacopeia.

^a^ Wheat middlings as carrier.

^b^ Calcium carbonate as carrier.

Table D-2 Vitamins and Minerals in NTP-2000 Rat and Mouse Ration^a^

| Amount | Source
Vitamins
A | 4,000 IU | Stabilized vitamin A palmitate or acetate
D | 1,000 IU | D-activated animal sterol
K | 1.0 mg | Menadione sodium bisulfite complex
α-Tocopheryl Acetate | 100 IU | –
Niacin | 23 mg | –
Folic Acid | 1.1 mg | –
d-Pantothenic Acid | 10 mg | d-Calcium pantothenate
Riboflavin | 3.3 mg | –
Thiamine | 4 mg | Thiamine mononitrate
B_12_ | 52 μg | –
Pyridoxine | 6.3 mg | Pyridoxine hydrochloride
Biotin | 0.2 mg | d-Biotin
Minerals
Magnesium | 514 mg | Magnesium oxide
Iron | 35 mg | Iron sulfate
Zinc | 12 mg | Zinc oxide
Manganese | 10 mg | Manganese oxide
Copper | 2.0 mg | Copper sulfate
Iodine | 0.2 mg | Calcium iodate
Chromium | 0.2 mg | Chromium acetate

^a^ Per kg of finished product.

Table D-3 Nutrient Composition of NTP-2000 Rat and Mouse Ration (Blasting Sand)

Nutrient | Mean ± Standard Deviation | Range | Number of Samples
Protein (% by Weight) | 14.4 ± 0.33 | 13.7–14.8 | 11
Crude Fat (% by Weight) | 8.2 ± 0.27 | 7.7–8.5 | 11
Crude Fiber (% by Weight) | 9.4 ± 1.19 | 7.1–11.1 | 11
Ash (% by Weight) | 5.1 ± 0.10 | 4.93–5.21 | 11
Amino Acids (% of Total Diet)
Arginine | 0.783 ± 0.070 | 0.670–0.970 | 22
Cystine | 0.220 ± 0.024 | 0.150–0.250 | 22
Glycine | 0.701 ± 0.041 | 0.620–0.800 | 22
Histidine | 0.352 ± 0.077 | 0.270–0.680 | 22
Isoleucine | 0.546 ± 0.044 | 0.430–0.660 | 22
Leucine | 1.095 ± 0.067 | 0.960–1.240 | 22
Lysine | 0.711 ± 0.114 | 0.310–0.860 | 22
Methionine | 0.409 ± 0.046 | 0.260–0.490 | 22
Phenylalanine | 0.628 ± 0.040 | 0.540–0.720 | 22
Threonine | 0.505 ± 0.043 | 0.430–0.610 | 22
Tryptophan | 0.150 ± 0.028 | 0.110–0.200 | 22
Tyrosine | 0.401 ± 0.061 | 0.280–0.540 | 22
Valine | 0.665 ± 0.043 | 0.550–0.730 | 22
Essential Fatty Acids (% of Total Diet)
Linoleic | 3.95 ± 0.259 | 3.49–4.55 | 22
Linolenic | 0.30 ± 0.032 | 0.21–035 | 22
Vitamins
Vitamin A (IU/kg) | 3,862 ± 95.8 | 2,110–5,120 | 11
Vitamin D (IU/kg) | 1,000^a^ | – | –
α-Tocopherol (ppm) | 80.6 ± 22.03 | 27.0–124.0 | 22
Thiamine (ppm)^b^ | 7.5 ± 1.35 | 6.1–11.0 | 11
Riboflavin (ppm) | 7.6 ± 2.89 | 4.20–17.50 | 22
Niacin (ppm) | 78.9 ± 9.08 | 66.4–98.2 | 22
Pantothenic Acid (ppm) | 26.9 ± 12.63 | 17.4–81.0 | 22
Pyridoxine (ppm)^b^ | 9.54 ± 1.99 | 6.44–13.7 | 22
Folic Acid (ppm) | 1.62 ± 0.48 | 1.15–3.27 | 22
Biotin (ppm) | 0.32 ± 0.10 | 0.2–0.704 | 22
Vitamin B_12_ (ppb) | 53.6 ± 39.6 | 18.3–174.0 | 22
Choline (ppm)^b^ | 2,846 ± 485 | 1,820–3,790 | 22
Minerals
Calcium (%) | 0.889 ± 0.038 | 0.810–0.960 | 11
Phosphorus (%) | 0.542 ± 0.022 | 0.504–0.587 | 11
Potassium (%) | 0.666 ± 0.030 | 0.626–0.733 | 22
Chloride (%) | 0.386 ± 0.039 | 0.300–0.474 | 22
Sodium (%) | 0.189 ± 0.016 | 0.160–0.222 | 22
Magnesium (%) | 0.216 ± 0.062 | 0.185–0.490 | 22
Sulfur (%) | 0.170 ± 0.029 | 0.116–0.209 | 22
Iron (ppm) | 186 ± 39.21 | 135–311 | 22
Manganese (ppm) | 51.4 ± 10.28 | 21.0–73.1 | 22
Zinc (ppm) | 53.4 ± 8.46 | 43.3–78.5 | 22
Copper (ppm) | 7.01 ± 2.562 | 3.21–16.30 | 22
Iodine (ppm) | 0.503 ± 0.206 | 0.158–0.972 | 22
Chromium (ppm) | 0.694 ± 0.276 | 0.330–1.380 | 21
Cobalt (ppm) | 0.26 ± 0.164 | 0.098–0.864 | 20

^a^ From formulation.

^b^ As hydrochloride (thiamine and pyridoxine) or chloride (choline).

Table D-4 Contaminant Levels in NTP-2000 Rat and Mouse Ration (Blasting Sand)^a^

| Mean ± Standard Deviation^b^ | Range | Number of Samples
Contaminants
Arsenic (ppm) | 0.24 ± 0.046 | 0.169–0.307 | 11
Cadmium (ppm) | 0.06 ± 0.005 | 0.053–0.069 | 11
Lead (ppm) | 0.15 ± 0.243 | 0.064–0.887 | 11
Mercury (ppm) | <0.02 | – | 11
Selenium (ppm) | 0.23 ± 0.055 | 0.16–0.342 | 11
Aflatoxins (ppb) | <5.00 | – | 11
Nitrate Nitrogen (ppm)^c^ | 23.7 ± 9.37 | 10.0–35.9 | 11
Nitrite Nitrogen (ppm)^c^ | <0.61 | – | 11
BHA (ppm)^d^ | <1.0 | – | 11
BHT (ppm)^d^ | <1.0 | – | 11
Aerobic Plate Count (CFU/g) | 10 ± 0.0 | 10 | 11
Coliform (MPN/g) | 3.0 ± 0.0 | 3.0 | 11
Escherichia coli (MPN/g) | <10 | – | 11
Salmonella (MPN/g) | Negative | – | 11
Total Nitrosoamines (ppb)^e^ | 11.2 ± 3.82 | 6.1–17.2 | 11
N-Nitrosodimethylamine (ppb)^e^ | 4.25 ± 3.424 | 1.1–11.1 | 11
N-Nitrosopyrrolidine (ppb)^e^ | 8.13 ± 2.427 | 5.0–11.0 | 11
Pesticides (ppm)
α-BHC | <0.01 | – | 11
β-BHC | <0.02 | – | 11
γ-BHC | <0.01 | – | 11
δ-BHC | <0.01 | – | 11
Heptachlor | <0.01 | – | 11
Aldrin | <0.01 | – | 11
Heptachlor Epoxide | <0.01 | – | 11
DDE | <0.01 | – | 11
DDD | <0.01 | – | 11
DDT | <0.01 | – | 11
HCB | <0.01 | – | 11
Mirex | <0.01 | – | 11
Methoxychlor | <0.05 | – | 11
Dieldrin | <0.01 | – | 11
Endrin | <0.01 | – | 11
Telodrin | <0.01 | – | 11
Chlordane | <0.05 | – | 11
Toxaphene | <0.10 | – | 11
Estimated PCBs | <0.20 | – | 11
Ronnel | <0.01 | – | 11
Ethion | <0.02 | – | 11
Trithion | <0.05 | – | 11
Diazinon | <0.10 | – | 11
Methyl Chlorpyrifos | 0.186 ± 0.144 | 0.02–0.553 | 11
Methyl Parathion | <0.02 | – | 11
Ethyl Parathion | <0.02 | – | 11
Malathion | 0.115 ± 0.119 | 0.020–0.395 | 11
Endosulfan I | <0.01 | – | 11
Endosulfan II | <0.01 | – | 11
Endosulfan Sulfate | <0.03 | – | 11

CFU = colony-forming units; MPN = most probable number; BHC = hexachlorocyclohexane or benzene hexachloride; PCB = polychlorinated biphenyl.

^a^ All samples were irradiated.

^b^ For values less than the limit of detection, the detection limit is given as the mean.

^c^ Sources of contamination: alfalfa, grains, and fish meal.

^d^ Sources of contamination: soy oil and fish meal.

^e^ All values were corrected for percent recovery.

Table D-5 Nutrient Composition of NTP-2000 Rat and Mouse Ration (Specular Hematite)

Nutrient | Mean ± Standard Deviation | Range | Number of Samples
Protein (% by Weight) | 14.6 ± 0.26 | 14.1–15.0 | 11
Crude Fat (% by Weight) | 8.3 ± 0.27 | 7.7–8.6 | 11
Crude Fiber (% by Weight) | 9.5 ± 1.25 | 7.1–11.1 | 11
Ash (% by Weight) | 5.0 ± 0.10 | 4.88–5.21 | 11
Amino Acids (% of Total Diet)
Arginine | 0.783 ± 0.070 | 0.670–0.970 | 22
Cystine | 0.220 ± 0.024 | 0.150–0.250 | 22
Glycine | 0.701 ± 0.041 | 0.620–0.800 | 22
Histidine | 0.352 ± 0.077 | 0.270–0.680 | 22
Isoleucine | 0.546 ± 0.044 | 0.430–0.660 | 22
Leucine | 1.095 ± 0.067 | 0.960–1.240 | 22
Lysine | 0.711 ± 0.114 | 0.310–0.860 | 22
Methionine | 0.409 ± 0.046 | 0.260–0.490 | 22
Phenylalanine | 0.628 ± 0.040 | 0.540–0.720 | 22
Threonine | 0.505 ± 0.043 | 0.430–0.610 | 22
Tryptophan | 0.150 ± 0.028 | 0.110–0.200 | 22
Tyrosine | 0.401 ± 0.061 | 0.280–0.540 | 22
Valine | 0.665 ± 0.043 | 0.550–0.730 | 22
Essential Fatty Acids (% of Total Diet)
Linoleic | 3.95 ± 0.259 | 3.49–4.55 | 22
Linolenic | 0.30 ± 0.032 | 0.21–0.35 | 22
Vitamins
Vitamin A (IU/kg) | 3,776 ± 93.5 | 2,110–5,330 | 11
Vitamin D (IU/kg) | 1,000^a^
α-Tocopherol (ppm) | 80.6 ± 22.03 | 27.0–124.0 | 22
Thiamine (ppm)^b^ | 7.8 ± 1.25 | 6.4–11.0 | 11
Riboflavin (ppm) | 7.6 ± 2.89 | 4.20–17.50 | 22
Niacin (ppm) | 78.9 ± 9.08 | 66.4–98.2 | 22
Pantothenic Acid (ppm) | 26.9 ± 12.63 | 17.4–81.0 | 22
Pyridoxine (ppm)^b^ | 9.54 ± 1.99 | 6.44–13.7 | 22
Folic Acid (ppm) | 1.62 ± 0.48 | 1.15–3.27 | 22
Biotin (ppm) | 0.32 ± 0.10 | 0.2–0.704 | 22
Vitamin B_12_ (ppb) | 53.6 ± 39.6 | 18.3–174.0 | 22
Choline (ppm)^b^ | 2,846 ± 485 | 1,820–3,790 | 22
Minerals
Calcium (%) | 0.887 ± 0.040 | 0.810–0.960 | 11
Phosphorus (%) | 0.546 ± 0.022 | 0.504–0.587 | 11
Potassium (%) | 0.666 ± 0.030 | 0.626–0.733 | 22
Chloride (%) | 0.386 ± 0.039 | 0.300–0.474 | 22
Sodium (%) | 0.189 ± 0.066 | 0.160–0.222 | 22
Magnesium (%) | 0.216 ± 0.062 | 0.185–0.490 | 22
Sulfur (%) | 0.170 ± 0.029 | 0.116–0.209 | 22
Iron (ppm) | 186 ± 39.21 | 135–311 | 22
Manganese (ppm) | 51.4 ± 10.28 | 21.0–73.1 | 22
Zinc (ppm) | 53.4 ± 8.46 | 43.3–78.5 | 22
Copper (ppm) | 7.01 ± 2.562 | 3.21–16.30 | 22
Iodine (ppm) | 0.503 ± 0.206 | 0.158–0.972 | 22
Chromium (ppm) | 0.694 ± 0.276 | 0.330–1.380 | 21
Cobalt (ppm) | 0.26 ± 0.164 | 0.098–0.864 | 20

^a^ From formulation.

^b^ As hydrochloride (thiamine and pyridoxine) or chloride (choline).

Table D-6 Contaminant Levels in NTP-2000 Rat and Mouse Ration (Specular Hematite)^a^

| Mean ± Standard Deviation^b^ | Range | Number of Samples
Contaminants
Arsenic (ppm) | 0.26 ± 0.021 | 0.240–0.307 | 11
Cadmium (ppm) | 0.06 ± 0.005 | 0.053–0.069 | 11
Lead (ppm) | 0.15 ± 0.243 | 0.064–0.887 | 11
Mercury (ppm) | <0.02 | – | 11
Selenium (ppm) | 0.22 ± 0.054 | 0.166–0.342 | 11
Aflatoxins (ppb) | <5.00 | – | 11
Nitrate Nitrogen (ppm)^c^ | 22.1 ± 8.53 | 10.0–35.9 | 11
Nitrite Nitrogen (ppm)^c^ | <0.61 | – | 11
BHA (ppm)^d^ | <1.0 | – | 11
BHT (ppm)^d^ | <1.0 | – | 11
Aerobic Plate Count (CFU/g) | 10 ± 0.0 | 10 | 11
Coliform (MPN/g) | 3.0 ± 0.0 | 3.0 | 11
Escherichia coli (MPN/g) | <10 | – | 11
Salmonella (MPN/g) | Negative | – | 11
Total Nitrosoamines (ppb)^e^ | 10.7 ± 4.03 | 5.6–16.2 | 11
N-Nitrosodimethylamine (ppb)^e^ | 3.36 ± 2.462 | 1.0–9.6 | 11
N-Nitrosopyrrolidine (ppb)^e^ | 7.68 ± 2.420 | 4.6–11.2 | 11
Pesticides (ppm)
α-BHC | <0.01 | – | 11
β-BHC | <0.02 | – | 11
γ-BHC | <0.01 | – | 11
δ-BHC | <0.01 | – | 11
Heptachlor | <0.01 | – | 11
Aldrin | <0.01 | – | 11
Heptachlor Epoxide | <0.01 | – | 11
DDE | <0.01 | – | 11
DDD | <0.01 | – | 11
DDT | <0.01 | – | 11
HCB | <0.01 | – | 11
Mirex | <0.01 | – | 11
Methoxychlor | <0.05 | – | 11
Dieldrin | <0.01 | – | 11
Endrin | <0.01 | – | 11
Telodrin | <0.01 | – | 11
Chlordane | <0.05 | – | 11
Toxaphene | <0.10 | – | 11
Estimated PCBs | <0.20 | – | 11
Ronnel | <0.01 | – | 11
Ethion | <0.02 | – | 11
Trithion | <0.05 | – | 11
Diazinon | <0.10 | – | 11
Methyl Chlorpyrifos | 0.173 ± 0.153 | 0.02–0.553 | 11
Methyl Parathion | <0.02 | – | 11
Ethyl Parathion | <0.02 | – | 11
Malathion | 0.147 ± 0.113 | 0.020–0.395 | 11
Endosulfan I | <0.01 | – | 11
Endosulfan II | <0.01 | – | 11
Endosulfan Sulfate | <0.03 | – | 11

CFU = colony-forming units; MPN = most probable number; BHC = hexachlorocyclohexane or benzene hexachloride; PCB = polychlorinated biphenyl.

^a^ All samples were irradiated.

^b^ For values less than the limit of detection, the detection limit is given as the mean.

^c^ Sources of contamination: alfalfa, grains, and fish meal.

^d^ Sources of contamination: soy oil and fish meal.

^e^ All values were corrected for percent recovery.