# Appendix C Chemical Characterization and Generation of Chamber Concentrations

## C.1 Procurement and Characterization

The blasting sand (coarse silica sand #2340) used in the 2-week and 39-week studies was obtained from Waupaca Sand and Solutions (Division of Faulks Brothers Construction Inc.; Waupaca, WI) [struck: Midwest Research Institute (MRI; Kansas City, MO)] in one lot by Midwest Research Institute (MRI; Kansas City, MO) and was assigned the lot number W100604JB. The micronized specular hematite (Barshot 50) used in the 2-week and 39-week studies was obtained from Opta Minerals (Waterdown, ON, Canada) [struck: MRI] in one lot (0101005CJ) by MRI (Kansas City, MO). The coal slag used in the 2-week study was obtained from Reed Minerals-Harsco Corporation (LaCygne, KS) [struck: MRI] in one lot (R042805KA). The crushed glass (VitroGrit^TM^ #30/50) used in the 2-week study was obtained from TriVitro Corporation (Kent, WA) [struck: MRI] in one lot (T092205KA). The garnet used in the 2-week study was obtained from Emerald Creek Garnet Ltd. (Fernwood, ID) [struck: MRI] in one lot (031605).^c^ Identity and purity analyses were conducted by multiple analytical chemistry laboratories and the study laboratory at Battelle Toxicology Northwest (Richland, WA). Reports on analyses performed in support of the abrasive blasting agent studies are on file at the National Institute of Environmental Health Sciences (NIEHS).

c ERRATUM: An error was identified in the NTP Toxicity Report on Abrasive Blasting Agents (TOX 91). The reported supplier information for each blasting agent has been corrected and trade names were added to the text in the HTML and PDF versions of this report; new information is italicized. [September 1, 2022]

### C.1.1 Blasting Sand

Prior to use in the studies, the particle size of blasting sand (lot W100604JB) was reduced by aqueous ball milling for 24 hours, followed by 5 hours of aqueous bead milling of 40/57/3 test material/water/ethanol (weight/weight/weight) by Aveka, Inc. (Woodbury, MN). The milled material was mixed with water and the mixture was dispersed under strong agitation and then spray dried.^d^ Lot W100604JB of blasting sand, a finely ground, gray powder, was expected to contain 90% to 100% silicon dioxide, with 49% to 90% of it being crystalline silica (SiO_2_).^1,5^ The test article was characterized and the composition was determined using analyses that included weight loss on drying (study laboratory); density (Quantachrome Instruments, Boynton Beach, FL); surface area by the Brunauer-Emmett-Teller (BET) surface area method using method A (Clear Science, Inc., Minneapolis, MN); Fourier transform infrared (FTIR) spectroscopy (EMSL Analytical, Inc., Westmont, NJ); inductively coupled plasma/atomic emission spectroscopy (ICP/AES) by method B for the identification and quantitation of silicon (Si) (study laboratory); proton induced X-ray emission (PIXE) spectroscopy to quantitate concentrations of major and minor elements (Elemental Analysis, Inc., Lexington, KY); powder X-ray diffraction (XRD) by methods C and D (EMSL Analytical, Inc., and H & M Analytical Services, Inc., Allentown, NJ, respectively), to identify and quantitate crystalline phases present at greater than 1%; and X-ray fluorescence (XRF) analyses for qualitative phase identification measurements using a SPECTRO iQ II spectrometer (SPECTRO Analytical Instruments GmbH., Kleve, Germany) with palladium radiation (H & M Analytical Services, Inc.). All spectra were consistent with the expected composition of blasting sand. A representative XRD spectrum is presented in Figure C-1.

d ERRATUM: An error was identified in the NTP Toxicity Report on Abrasive Blasting Agents (TOX 91). Text describing the bulk material preparation of blasting sand was added in the HTML and PDF versions of this report; new information is italicized. [September 1, 2022]

(A) For BET surface area analysis including an adsorption/desorption isotherm, the samples were degassed at 90°C for 1 hour and 150°C (specular hematite) or 250°C (blasting sand, coal slag, crushed glass, and garnet) for 13 hours and then analyzed using a system that included a Micromeritics Gemini 2375 Surface Area Analyzer (Micromeritics Instrument Corporation, Norcross, GA), UHP nitrogen (adsorbate gas), liquid nitrogen (cryogen), a pressure sequence of 16 adsorption points from 0.01 P/P_0_ to 0.995 P/P_0_ and 11 desorption points from 0.995 P/P_0_ to 0.5 P/P_0_, and an evacuation time of 3 minutes. A kaolinite standard reference material was included in the analysis.

(B) For ICP/AES analysis, standards obtained from the National Institute of Standards and Technology (NIST) were added to samples of the milled bulk material and the samples were subjected to room temperature and heated 55°C to 80°C acid digestions in a matrix of nitric acid (HNO_3_)/hydrofluoric acid (HF). After an additional heated 55°C to 80°C digestion in boric acid (H_3_BO_3_), hydroxylamine hydrochloride (NH_2_OH·HCl) was added to dissolve any metal oxides that may have remained, and the samples were analyzed on a Thermo Elemental IRIS Intrepid II instrument (Thermo Electron Corporation, Waltham, MA). Total Si content was quantitated by measurement of atomic emission at 212.412 nm; the internal standard cobalt (Co) was quantitated at 228.16 nm.

(C) XRD analysis conducted by EMSL Analytical, Inc., included a Rigaku D/Max-B diffractometer (Rigaku Americas Corporation, Lake Oswego, OR) equipped with a copper (Cu) X-ray tube and utilized National Institute for Occupational Safety and Health (NIOSH) Method 7500 (modified for bulk samples) to determine the concentration of crystalline silica.

(D) XRD analysis conducted by H & M Analytical Services, Inc., included a Philips PW1830 (Philips Analytical, San Francisco, CA), Siemens D5000 (Siemens, Munich, Germany), or PANalytical X’Pert Pro MPD (PANalytical B.V., Almelo, Netherlands) diffractometer with Cu radiation at 40 KV/30 mA or 45 KV/40 mA over the angular range of 10° to 70° with step sizes of 0.02° to 0.032° and counting times of 5 to 1,500 seconds per step or 8 hours per sample with a detection limit of 0.5% for the trace phases. The crystalline phases were identified using the Powder Diffraction File (International Centre for Diffraction Data) and quantitated using Rietveld refinement.

Lot W100604JB was determined to have a density of 2.78 g/cc and a BET surface area of approximately 20 m^2^/g; weight loss on drying indicated a water content of less than 1% for the bulk material. FTIR, ICP/AES, PIXE, and XRD Rietveld analyses indicated 39.0%, 39.4%, 37.7%, and 40.7% Si, respectively; the NIOSH method 7500 silicon result (29.5%) was inconsistent with the other Si content data. PIXE identified other elements above 1% as aluminum (Al, 2.0% to 2.2%), calcium (Ca, 1.3% to 1.4%), and iron (Fe, 1.1% to 1.3%), and elements approaching concentrations near 1% as magnesium (Mg, 0.6% to 0.8%), potassium (K, 0.8% to 0.9%), and zirconium (Zr, 0.7% to 0.8%). The test material phases were mostly crystalline quartz (SiO_2_, 76.4% to 78.5%) with cristobalite (0.6% to 0.8%) and crystalline impurities of calcite (CaCO_3_, 0.3% to 0.8%), dolomite [CaMg (CO_3_)_2_, 7.0% to 7.6%], and one phase tentatively identified as sanidine [K(AlSi_3_)O_8_, 12.7% to 15.1%] as determined through XRD Rietveld analysis.

To ensure stability, the bulk test material was stored at room temperature in safety-coated amber glass containers with Teflon^®^-lined caps. Periodic reanalyses of the test material were performed by the analytical chemistry and study laboratories during the 2-week and 39-week studies with ICP/AES, PIXE (2-week study only), and XRD, and no degradation of the test material was detected.

### C.1.2 Coal Slag

Prior to use in the studies, the particle size of coal slag (lot R042805KA) was reduced by aqueous ball milling for up to 27 hours, followed by 16 hours of aqueous bead milling of 50/50 test material/water (weight/weight) by Aveka, Inc. (Woodbury, MN). The milled material was mixed with water and the mixture was dispersed under strong agitation and then spray dried.^e^ Lot R042805KA of coal slag, a black, mostly amorphous powder was expected to contain 45% to 51% SiO_2_ with less than 1% of it being crystalline silica.^9^ The test article was characterized and the composition was determined using analyses that included weight loss on drying (study laboratory and Galbraith Laboratories, Inc., Knoxville, TN); Karl Fischer titration for water content (Galbraith Laboratories, Inc.); density (Quantachrome Instruments); BET surface area by method A (Clear Science, Inc.); ICP/AES by method B for the identification and quantitation of total Si, and also total Al, Fe, and Ca by measurement of atomic emission at 309.271, 259.940, and 317.933 nm, respectively (study laboratory); PIXE spectroscopy to quantitate concentrations of major and minor elements (Elemental Analysis, Inc.); powder XRD by a method similar to method D to identify and quantitate crystalline phases present at greater than 1% (H & M Analytical Services, Inc.); XRF for qualitative phase identification (H & M Analytical Services, Inc.); and carbon content using coulometric titration [samples were combusted using a LECO induction furnace (LECO Corporation, St. Joseph, MI) at greater than1,400°C in an oxygen atmosphere, acidified, and automatically titrated with a Model 5010 carbon dioxide coulometer (Coulometrics, Inc., Joliet, IL)] (Galbraith Laboratories, Inc.). Weight loss on drying and Karl Fischer titration analyses were performed on both dried (to constant weight) and undried samples of the test article. Samples for density, ICP/AES, PIXE, XRD, and XRF analyses were dried to a constant weight before their submission to the analytical chemistry laboratories for analysis. The samples for BET analysis were dried at the analytical chemistry laboratory before analysis, and the samples for carbon analysis were not dried. All spectra were consistent with the expected composition of coal slag. A representative XRD spectrum is presented in Figure C-2.

e ERRATUM: An error was identified in the NTP Toxicity Report on Abrasive Blasting Agents (TOX 91). Text describing the bulk material preparation of coal slag was added in the HTML and PDF versions of this report; new information is italicized. [September 1, 2022]

Lot R042805KA was determined to have a density of 2.77 g/cc and a BET surface area of approximately 9.26 m^2^/g. An initial weight loss on drying experiment yielded an average weight loss of 15.3% for the bulk test article; additional samples of the test article were dried to constant weight, and the average weight loss was 17.4%. Karl Fischer titration of the undried test article (11.7% water) compared favorably with a concurrent weight loss on drying measurement (13.2% water). Samples of the dried test article underwent an additional weight loss on drying assessment and Karl Fischer analysis; the mean percent weight loss and water content were both less than or equal to 1%. ICP/AES and PIXE analyses indicated 21.7% and 21.5% Si, respectively. Other elements identified at values greater than 1% were Al, Fe, and Ca by ICP/AES at 9.9%, 8.1%, and 10.7%, respectively, and by PIXE at 10.0%, 7.2%, and 9.1%, respectively. PIXE values for other elements near 1% were Mg (1.6%) and K (0.71%). No crystalline silica was detected; the only crystalline phase detected was CaCO_3_ at a 1.2% weight fraction as determined through the XRD Rietveld analysis. Coulometric analysis indicated 0.127% carbon.

To ensure stability, the bulk test material (dried to constant weight and sieved) was stored at room temperature in safety-coated amber glass containers with Teflon-lined caps. Periodic reanalyses of the test material were performed by the analytical chemistry and study laboratories during the 2-week study with ICP/AES, PIXE, and XRD, and no degradation of the test material was detected.

### C.1.3 Crushed Glass

Prior to use in the studies, the particle size of crushed glass (lot T092205KA) was reduced by aqueous ball milling for up to 27 hours, followed by 35 hours of aqueous bead milling of 50/50 test material/water (weight/weight) by Aveka, Inc. (Woodbury, MN). The milled material was mixed with water and the mixture was dispersed under strong agitation and then spray dried. The final material was oven dried at 200°C for 8 hours.^f^ Lot T092205KA of crushed glass, a mostly amorphous powder, was expected to contain approximately 72.5% SiO_2_, with none of it being crystalline silica.^9^ The test article was characterized and the composition was determined by weight loss on drying (study laboratory and Galbraith Laboratories, Inc.); using Karl Fischer titration for water content (Galbraith Laboratories, Inc.); density (Quantachrome Instruments); BET surface area by method A (Clear Science, Inc.); ICP/AES by method B for the identification and quantitation of total Si, Al, Fe, and Ca as described for coal slag and also total sodium (Na), Mg, and K by measurement of atomic emission at 589.592, 279.553, and 766.491 nm, respectively (study laboratory); PIXE spectroscopy to quantitate concentrations of major and minor elements (Elemental Analysis, Inc.); and powder XRD by a method similar to method D to identify and quantitate crystalline phases (H & M Analytical Services, Inc.). Due to the presence of unidentified phases at less than 1%, the Reference Intensity Ratio (RIR) method was used to quantify the weight fractions of the XRD phases detected. All spectra were consistent with the expected composition of crushed glass; a representative XRD spectrum is presented in Figure C-3.

f ERRATUM: An error was identified in the NTP Toxicity Report on Abrasive Blasting Agents (TOX 91). Text describing the bulk material preparation of crushed glass was added in the HTML and PDF versions of this report; new information is italicized. [September 1, 2022]

Lot T092205KA was determined to have a density of 2.39 g/cc and a BET surface area of approximately 22.4 m^2^/g. Weight loss on drying indicated a water content of less than 1%, but Karl Fischer titration averaged 3.5% water. Additional weight loss on drying analysis at an elevated oven temperature averaged 3.1% water, confirming the presence of tightly bound water in the bulk test article. ICP/AES and PIXE analyses indicated 31.2% and 28.9% Si, respectively; the percent values for Ca, Na, Mg, Al, Fe, and K by ICP/AES were 5.5%, 9.3%, 1.9%, 0.3%, 0.1%, and 0.2%, respectively; PIXE values for these elements were 5.6%, 8.9%, 1.9%, 0.4%, 0.1%, and 0.2%, respectively. The test material appeared to be mostly amorphous (93% to 98%) with crystalline phases of natrite (Na_2_CO_3_, 0.4% to 1.6%), aragonite (orthorhombic CaCO_3_, 0.3% to 0.5%), calcite (hexagonal CaCO_3_, 0.7% to 1.5%), and quartz (SiO_2_, 0.2% to 0.8%) as determined through the XRD RIR method.

To ensure stability, the bulk test material was stored at room temperature in safety-coated amber glass containers with Teflon-lined caps. Periodic reanalyses of the test material were performed by the analytical chemistry and study laboratories during the 2-week study with ICP/AES, PIXE, and XRD, and no degradation of the test material was detected.

### C.1.4 Garnet

Prior to use in the studies, the particle size of garnet (lot 031605) was reduced by aqueous ball milling for up to 27 hours, followed by 20 hours of aqueous bead milling of 56/44 test material/water (weight/weight) by Aveka, Inc. (Woodbury, MN). The milled material was mixed with water and the mixture was dispersed under strong agitation and then spray dried.^g^ Lot 031605 of garnet, a red, mostly amorphous powder, was expected to contain 36% to 38% SiO_2_ with less than 0.8% of it being crystalline silica.^9^ The test article was characterized and the composition was determined using analyses that included weight loss on drying (study laboratory); Karl Fischer titration for water content (Galbraith Laboratories, Inc.), density (Quantachrome Instruments); BET surface area by method A (Clear Science, Inc.); ICP/AES by method B for the identification and quantitation of total Si, Al, Fe, and Mg as described for the analysis of crushed glass except that total mg was determined by measurement of atomic emission at 280.271 nm (study laboratory); PIXE spectroscopy to quantitate concentrations of major and minor elements (Elemental Analysis, Inc.); and powder XRD by a method similar to method D to identify and quantitate crystalline phases present at greater than 1% (H & M Analytical Services, Inc.). All spectra were consistent with the composition of garnet; a representative XRD spectrum is presented in Figure C-4.

g ERRATUM: An error was identified in the NTP Toxicity Report on Abrasive Blasting Agents (TOX 91). Text describing the bulk material preparation of garnet was added in the HTML and PDF versions of this report; new information is italicized. [September 1, 2022]

Lot 031605 was determined to have a density of approximately 4.0 g/cc and a BET surface area of approximately 22.2 m^2^/g. Weight loss on drying and Karl Fischer titration indicated 1.7% and 1.0% water, respectively, for the bulk material. ICP/AES, PIXE, and XRD analyses indicated 16.7%, 17.5%, and 18.8% Si, respectively; ICP/AES values for Al, Fe, and mg were 10.6%, 22.5%, and 1.4%, respectively; PIXE values for these elements were 11.3%, 23.3%, and 1.5%, respectively. The test material was mostly crystalline garnet [general formula A_3_ B_2_ (SiO_4_)_3_, in which A is Fe and/or Mg and B is Al and/or Fe (note: compare with almandine in Figure C-4); 89%] with crystalline components of quartz (SiO_2_, 6%) and staurolite (HFe_2_Al_9_Si_4_O_24_, 5% to 6%) as determined through the XRD Rietveld method.

To ensure stability, the bulk test material was stored at room temperature in safety-coated amber glass containers with Teflon-lined caps. Periodic reanalyses of the test material were performed by the analytical chemistry and study laboratories during the 2-week study with ICP/AES, PIXE, and XRD, and no degradation of the test material was detected.

### C.1.5 Specular Hematite

Prior to use in the studies, the particle size of specular hematite (lot O101005CJ) was reduced by aqueous ball milling for up to 27 hours, followed by 30 hours of aqueous bead milling of 60/40 test material/water (weight/weight) by Aveka, Inc. (Woodbury, MN). The milled material was mixed with water and the mixture was dispersed under strong agitation and then spray dried. The spray-dried material was oven dried at 200°C for 8 hours.^h^ Lot O101005CJ of specular hematite, a finely divided, red powder, was expected to contain less than 1% of crystalline silica Paumanok, 1992. The test article was characterized and the composition was determined using analyses that included weight loss on drying (study laboratory); Karl Fischer titration for water content (Galbraith Laboratories, Inc.); density (Quantachrome Instruments); BET surface area by method A (Clear Science, Inc.); ICP/AES by a method similar to method B [except that the initial room temperature digestion used hydrochloric acid (HCl), subsequent digestions in HNO_3_/HF and H_3_BO_3_ were conducted in a microwave (200°C and 150°C, respectively), and NH_2_OH·HCL was not used to dissolve remaining metal oxides]. The samples were then analyzed for the identification and quantitation of total Si, Al, and Fe as described for the analysis of coal slag, and also total Zr by measurement of atomic emission at 339.198 nm (study laboratory); PIXE spectroscopy to quantitate concentrations of major and minor elements (Elemental Analysis, Inc.); and powder XRD by method E (H & M Analytical Services, Inc.) to identify and quantitate crystalline phases present at greater than 1%. All spectra were consistent with the expected composition of specular hematite; a representative XRD spectrum is presented in Figure C-5.

h ERRATUM: An error was identified in the NTP Toxicity Report on Abrasive Blasting Agents (TOX 91). Text describing the bulk material preparation of specular hematite was added in the HTML and PDF versions of this report; new information is italicized. [September 1, 2022]

(E) For XRD analysis, a Philips PW3020 diffractometer (Philips Analytical, San Francisco, CA) or PANalytical X’Pert Pro MPD diffractometer (PANalytical B.V.) was used, with Cu radiation at 40 KV/30 mA or 45 KV/40 mA over angular ranges of 10° or 20° to 70° with step sizes of 0.0156° or 0.05° and counting times of 40 seconds per step or 3.5 to 6.5 hours per sample with a detection limit of approximately 0.5% for the trace phases. The crystalline phases were identified using the Powder Diffraction File (International Centre for Diffraction Data) and quantitated using Rietveld refinement.

Lot O101005CJ was determined to have a density of approximately 5 g/cc and a BET surface area of approximately 18.2 m^2^/g. Weight loss on drying and Karl Fischer titration both indicated less than 1% water for the bulk test material. ICP/AES, PIXE, and XRD analyses indicated the presence of Fe at approximately 69.4%, 63.4%, and 69.1%, respectively. ICP/AES values for Si, Al, and Zr were 1.2%, 0.4%, and 0.6%, and PIXE values for these elements were 1.2%, 0.4%, and 0.5%, respectively. The test material was crystalline with phases of specular hematite (Fe_2_O_3_, approximately 96%), magnetite (Fe_3_O_4_, 2% to 3%), and quartz (SiO_2_, 1% to 2%), as determined through the XRD Rietveld method.

To ensure stability, the bulk test material was stored at room temperature in safety-coated amber glass containers with Teflon-lined caps. Periodic reanalyses of the test material were performed by the analytical chemistry and study laboratories during the 2-week and 39-week studies with ICP/AES and XRD, and no degradation of the test material was detected.

## C.2 Aerosol Generation and Exposure Systems

Schematic diagrams of the aerosol generation and distribution systems used in the abrasive blasting agent studies are shown in Figure C-6 through Figure C-10.

For the 2-week studies of abrasive blasting agents, the aerosol generation system consisted of a linear feed dust-metering device designed and built by Battelle to meter the abrasive blasting agent from a reservoir into an air stream for aerosolization. Within the metering device, periodic blasts of compressed air suspended small volumes of blasting sand, coal slag, crushed glass, garnet, or specular hematite in the air stream for transport to the metering device exhaust tube. For blasting sand (Figure C-6), coal slag, and garnet (Figure C-7), a jet disperser was positioned immediately downstream from the metering device exhaust tube. For coal slag and garnet, the jet disperser was followed by a particle attrition chamber (PAC) to enhance the aerosolization of the test material. For crushed glass (Figure C-8) and specular hematite (Figure C-9), a Trost jet mill (Garlock, Inc., Newtown, PA), was used downstream from the metering device exhaust tube to perform initial particle size reduction; opposing compressed air gas streams drove the jet mill.

All generation system components were housed in a glove box in the control center room. From the jet disperser (blasting sand, coal slag, garnet), jet mill (crushed glass, specular hematite) aerosol was blended with filtered, compressed air before it was conveyed down the distribution line from the control center room to the exposure room. For crushed glass, as the air stream entered the exposure room, an in-line cyclone separator was used to further decrease particle size and extract nonrespirable aerosol. For blasting sand (2-week and 39-week studies), coal slag, crushed glass, garnet, and the 39-week study of specular hematite, all chambers in the exposure room except for the control were fed aerosol from a single distribution line constructed of stainless steel, bonded and grounded to prevent electrostatic charge buildup. For the 2-week study of specular hematite, the distribution line was split into north and south branches. Aerosol was supplied to the 60 mg/m^3^ chamber from the south distribution line branch; all remaining chambers in the exposure room except the control chamber were fed aerosol from the north distribution line branch. During exposures to all the abrasive blasting agents, the airflow through the distribution line was controlled using house vacuum regulated by a filter-protected flow meter. A second distribution line flow control system was available during off-exposure periods. This system consisted of a vacuum transducer pump (Air-Vac Engineering Company, Inc., Seymour, CT) of higher flow capacity, positioned in parallel with the flow meter control assembly and was operational only during critical shutdown periods. At each exposure chamber, aerosol was delivered from the distribution line by a sampling tube. The flow through each sampling tube was induced by a stainless-steel air ejector pump designed and fabricated by Battelle. The flow rate and configuration of the ejector pump and sampling tube combination were chosen to optimize the efficiency of the delivery system. The aerosol then entered the chamber inlet duct where it was further diluted with humidified, Parafil-, charcoal-, and high-efficiency particulate air (HEPA)-filtered air to achieve the desired exposure concentration.

The 39-week study of blasting sand used the same aerosol generation system described for the 2-week study of this test material (Figure C-6). For the 39-week study of specular hematite, the aerosol generation system (Figure C-10) was similar to that described for the 2-week study of blasting sand (Figure C-6) except for the additions of an in-line settling jar within the glove box and an in-line cyclone separator in the distribution line entering the exposure room as described for the 2-week study of crushed glass (Figure C-8).

The study laboratory designed the inhalation exposure chamber (Harford Systems Division of Lab Products, Inc., Aberdeen, MD) so that uniform aerosol concentrations could be maintained throughout the chamber with the catch pans in place. The total active mixing volume of each chamber was 1.7 m^3^.

## C.3 Aerosol Concentration Monitoring

Summaries of the chamber aerosol concentrations are given in Table C-1 and Table C-2. The concentration of the abrasive blasting agent in the exposure chambers and room air was monitored using two real-time aerosol monitors (RAMs) (Model RAM-1; MIE, Inc., Bedford, MA). The monitors were connected to the chambers by a sampling system designed by Battelle incorporating a valve that multiplexed each RAM to a 0 mg/m^3^ chamber or the room, a HEPA-filtered room air blank, and two exposure chambers. The output (voltage) of the RAM was recorded by a program designed by Battelle (Battelle Exposure Data Acquisition and Control) to select the correct sample stream and acquire a raw voltage signal from each RAM. Equations for the calibration curves resided within the program and were used to convert the measured RAM voltages to exposure chamber concentrations. Concentration control limits within the program were compared to each measured concentration and, if limits were exceeded, an audible alarm was triggered or, in extreme cases, exposure was terminated.

Each RAM was calibrated by constructing a response curve using the measured RAM voltages (voltage readings were corrected by subtracting the RAM zero-offset voltage from measured RAM voltages) and chamber concentrations of the abrasive blasting agents measured gravimetrically or specific to the test article on exposure chamber filters. Developmental studies demonstrated that gravimetric and test article-specific measurements of chamber concentrations were comparable. For all abrasive blasting agents, exposure chamber atmosphere samples were collected each day on 25 mm Pallflex Emfab TX40H120WW Teflon-coated, glass-fiber filters and on 25 mm, 0.45 μm GH Polypro polypropylene filters (both obtained from Pall Corporation, Ann Arbor, MI). Test article-specific assays of blasting sand, coal slag, crushed glass, and garnet measured the amount of Si captured on filters extracted with 1:3 HNO_3_:HF, and used an ICP/AES method otherwise similar to method B. Test article-specific assays of specular hematite measured the amount of Fe captured on filters extracted with HCl, also using an ICP/AES method similar to method B.

The ICP/AES instrument was calibrated against serially diluted NIST-traceable spectrometric standards of Si (for blasting sand, coal slag, crushed glass, and garnet) or Fe (for specular hematite) and the internal standard Co. Quality control standards and a reagent blank were analyzed after calibration, after approximately every 10th sample, and at the end of the analysis to determine accuracy and calibration drift during analysis.

## C.4 Chamber Atmosphere Characterization

Particle size distribution was determined once before the 2-week and 39-week studies began, once during the 2-week studies, and once a month during the 39-week studies. Samples were taken from each exposure chamber using a Mercer-style seven-stage cascade impactor (In-Tox Products, Moriarty, NM). For the 2-week studies of blasting sand, coal slag, crushed glass, and garnet, impactor samples were collected on polypropylene filters (GH Polypro, Pall Corporation), dissolved using HNO_3_, HF, H_3_BO_3_ and NH_2_OH·HCl, and assayed for Si using ICP/AES by a method otherwise similar to method B. For the 2-week study of specular hematite, impactor samples were collected on glass slides lightly coated with silicone to reduce particle bounce or on glass-fiber filters (Pallflex^®^ Emfab™, Pall Corporation), dissolved using HCl and sonication, and analyzed for Fe using ICP/AES by a method otherwise similar to method B. For the 39-week studies, impactor samples of blasting sand and specular hematite were collected on stainless-steel slides or glass-fiber filters (Pallflex Emfab, Pall Corporation) and then measured gravimetrically to determine the amount of test article deposited on each stage. The relative mass of each abrasive blasting agent collected on each stage was analyzed by the NEWCAS impactor analysis program developed at Battelle and was based on probit analysis.^50^ The resulting estimates of the mass median aerodynamic particle diameter and the geometric standard deviation of each set of samples collected during the studies are given in Table C-3 through Table C-5. All values of mass median aerodynamic diameter were less than 3 μm as required by the protocol.

Buildup and decay rates for chamber aerosol concentrations were determined with and without animals present in the chambers. At a chamber airflow rate of 15 air changes per hour, the theoretical value for the time to achieve 90% of the target concentration after the beginning of aerosol generation (T_90_) and the time for the chamber concentration to decay to 10% of the target concentration after aerosol generation was terminated (T_10_) was approximately 9.4 minutes. For the 2-week study of blasting sand, T_90_ and T_10_ values ranged from 9 to 10 minutes with animals present. For the 2-week studies of coal slag, crushed glass, garnet, and specular hematite, T_90_ values ranged from 10 to 13, 12 to 14, 13 to 15, and 9 to 22 minutes, respectively, with animals present; T_10_ values ranged from 9 to 10, 9 to 10, 10 to 11, and 10 to 11 minutes, respectively. For the 39-week study of blasting sand, T_90_ values ranged from 12 to 13 minutes without animals present and from 13 to 14 minutes with animals; T_10_ values ranged from 8 to 9 minutes without animals present and from 10 to 11 minutes with animals. For the 39-week study of specular hematite, T_90_ values ranged from 12 to 13 minutes without animals present and from 10 to 12 minutes with animals; T_10_ values were 9 minutes without animals present and ranged from 10 to 11 minutes with animals. A T_90_ value of 12 minutes was selected for all studies.

The uniformity of aerosol concentration in the inhalation exposure chambers without animals present was evaluated before the 39-week studies began; in addition, concentration uniformity with animals present in the chambers was measured once during the 2-week studies and three times during the 39-week studies. Aerosol concentrations were measured using the on-line monitor with the stream-selection valve fixed in one position to allow continuous monitoring from a single input line. Concentrations were measured at 12 chamber sample ports, one in front and one in back for each of six possible cage unit positions per chamber. Chamber concentration uniformity was maintained throughout the studies.

The persistence of the abrasive blasting agents in the chambers after aerosol delivery ended was determined by monitoring the concentration overnight in the 30 mg/m^3^ chambers (except for the 2-week and 39-week studies of specular hematite that monitored concentrations in the 60 mg/m^3^ chamber), with (all studies) and without (39-week studies only) animals present in the chambers. In the 2-week studies of blasting sand, coal slag, crushed glass, garnet, and specular hematite, the concentration decreased to less than 1% of the starting concentration within 19, 19, 21, 20, and 21 minutes, respectively. In the 39-week study of blasting sand, the concentration decreased to less than 1% of the starting concentration within 20 minutes with animals present and within 19 minutes without animals. In the 39-week study of specular hematite, the concentration decreased to less than 1% of the starting concentration within 21 minutes with animals present and within 18 minutes without animals.

Stability studies of the test materials in the generation and exposure systems were performed by the analytical chemistry and study laboratories. During the 2-week studies, before the start of the 39-week studies, and twice during the 39-week studies, blasting sand, coal slag, crushed glass, garnet, or specular hematite powder samples were taken from the low and high exposure concentration chambers and the aerosol distribution lines by collection on 25 mm A/E glass-fiber or polypropylene (GH Polypro) filters (Pall Corporation). On each sample collection day, samples of the bulk test material were collected before filling the generator reservoir and from the reservoir at the end of the generation day; additional test material was added to the generator each day. Samples were analyzed by XRD to identify and quantitate crystalline phases present in each abrasive blasting agent and by ICP/AES and PIXE (2-week studies of blasting sand, coal slag, crushed glass, and garnet) to determine elemental content, and carbon content was assayed by combustion (coal slag only). The analytical methods for these in-system stability assays were generally similar to those described earlier for initial characterization of each bulk test article. After accounting for minor inconsistencies introduced by changes in instrumentation and techniques, results of the XRD, ICP/AES, PIXE, and carbon in-system stability assays showed that the composition of each abrasive blasting agent in the exposure chambers and distribution lines was stable in the presence and absence of animals, reflected the composition of the bulk test material in the generator reservoir, and was generally comparable to that found during the initial characterization assays of each test article. These assays also indicated that contaminations from metal materials in the exposure generation systems did not occur.

Table C-1 Summary of Chamber Concentrations in the Two-week Inhalation Studies of Abrasive Blasting Agents in F344/NTac Rats

| Total Concentration (mg/m^3^) | Total Number of Readings | Average Concentration^a^ (mg/m^3^)
Blasting Sand | 3 | 127 | 3.0 ± 0.2
| 15 | 126 | 14.6 ± 0.6
| 30 | 127 | 30.5 ± 1.3
Coal Slag | 3 | 128 | 2.92 ± 0.21
| 15 | 126 | 14.9 ± 0.8
| 30 | 128 | 30.4 ± 1.8
Crushed Glass | 3 | 118 | 2.94 ± 0.12
| 15 | 119 | 15.0 ± 0.6
| 30 | 118 | 30.4 ± 0.9
Garnet | 3 | 119 | 2.87 ± 0.18
| 15 | 118 | 14.8 ± 0.9
| 30 | 119 | 29.8 ± 1.6
Specular Hematite | 3 | 117 | 2.92 ± 0.19
| 15 | 118 | 14.8 ± 1.0
| 30 | 118 | 29.5 ± 1.9
| 60 | 118 | 58.1 ± 3.5

^a^ Mean ± standard deviation.

Table C-2 Summary of Chamber Concentrations in the 39-week Inhalation Studies of Blasting Sand and Specular Hematite in Sprague Dawley Rats

| Total Concentration (mg/m^3^) | Total Number of Readings | Average Concentration^a^ (mg/m^3^)
Blasting Sand | 15 | 1,929 | 14.5 ± 1.0
| 30 | 1,916 | 29.2 ± 1.7
| 60 | 1,929 | 59.1 ± 3.3
Specular Hematite | 15 | 1,973 | 14.9 ± 0.9
| 30 | 1,966 | 29.5 ± 1.7
| 60 | 1,973 | 59.4 ± 3.1

^a^ Mean ± standard deviation.

Table C-3 Summary of Aerosol Size Measurements for the F344/NTac Rat Exposure Chambers in the Two-week Inhalation Studies of Abrasive Blasting Agents

| Target Concentration (mg/m^3^) | Mass Median Aerodynamic Diameter (μm) | Geometric Standard Deviation
Blasting Sand | 3 | 1.13 | 2.50
| 15 | 1.24 | 2.34
| 30 | 1.26 | 2.32
Coal Slag | 3 | 1.13 | 2.26
| 15 | 1.14 | 2.22
| 30 | 1.18 | 2.31
Crushed Glass | 3 | 1.0 | 2.6
| 15 | 1.1 | 2.7
| 30 | 1.1 | 2.5
Garnet | 3 | 1.1 | 2.4
| 15 | 1.0 | 2.4
| 30 | 1.1 | 2.4
Specular Hematite | 3 | 0.8 | 2.3
| 15 | 0.7 | 2.1
| 30 | 0.8 | 2.1
| 60 | 0.8 | 2.1

Table C-4 Summary of Aerosol Size Measurements for the Sprague Dawley Rat Exposure Chambers in the 39-week Inhalation Study of Blasting Sand

Date of Test | Target Concentration (mg/m^3^) | Mass Median Aerodynamic Diameter (μm) | Geometric Standard Deviation
April 2009 | 15 | 1.3 | 2.2
| 30 | 1.4 | 2.3
| 60 | 1.5 | 2.3
May 2009 | 15 | 1.3 | 2.4
| 30 | 1.1 | 2.6
| 60 | 1.3 | 2.6
June 2009 | 15 | 1.5 | 2.2
| 30 | 1.4 | 2.1
| 60 | 1.6 | 2.2
July 2009 | 15 | 1.3 | 2.5
| 30 | 1.6 | 2.2
| 60 | 1.6 | 2.5
August 2009 | 15 | 1.5 | 2.5
| 30 | 1.8 | 2.6
| 60 | 1.5 | 2.6
September 2009 | 15 | 1.0 | 2.1
| 30 | 1.8 | 2.3
| 60 | 1.4 | 2.1
October 2009 | 15 | 1.4 | 2.1
| 30 | 1.4 | 2.3
| 60 | 1.5 | 2.2
November 2009 | 15 | 1.3 | 2.6
| 30 | 1.6 | 2.7
| 60 | 1.5 | 2.1
December 2009 | 15 | 1.3 | 2.2
| 30 | 1.6 | 2.4
| 60 | 1.6 | 2.4
January 2010 | 15 | 1.4 | 2.2
| 30 | 1.3 | 2.4
| 60 | 1.8 | 2.8
Range | 15 | 1.0–1.5 | 2.1–2.6
| 30 | 1.1–1.8 | 2.1–2.7
| 60 | 1.3–1.8 | 2.1–2.8

Table C-5 Summary of Aerosol Size Measurements for the Sprague Dawley Rat Exposure Chambers in the 39-week Inhalation Study of Specular Hematite

Date of Test | Target Concentration (mg/m^3^) | Mass Median Aerodynamic Diameter (μm) | Geometric Standard Deviation
August 2009 | 15 | 0.9 | 2.3
| 30 | 1.0 | 2.2
| 60 | 1.0 | 2.1
September 2009 | 15 | 0.9 | 1.9
| 30 | 0.9 | 2.3
| 60 | 0.9 | 2.0
October 2009 | 15 | 0.8 | 2.0
| 30 | 1.0 | 2.1
| 60 | 0.9 | 1.9
November 2009 | 15 | 1.1 | 2.2
| 30 | 1.1 | 2.1
| 60 | 1.0 | 2.2
December 2009 | 15 | 0.9 | 2.4
| 30 | 1.1 | 2.3
| 60 | 0.9 | 2.0
January 2010 | 15 | 0.9 | 1.8
| 30 | 0.8 | 2.0
| 60 | 0.9 | 1.9
February 2010 | 15 | 0.9 | 2.1
| 30 | 1.0 | 2.5
| 60 | 1.1 | 2.3
March 2010 | 15 | 0.9 | 2.4
| 30 | 0.9 | 2.7
| 60 | 0.9 | 2.2
April 2010 | 15 | 1.0 | 2.1
| 30 | 0.9 | 2.1
| 60 | 1.1 | 2.0
Range | 15 | 0.8–1.1 | 1.8–2.4
| 30 | 0.8–1.1 | 2.0–2.7
| 60 | 0.9–1.1 | 1.9–2.3

Figure C-1

X-ray Diffraction Pattern of Blasting Sand

Figure C-2

X-ray Diffraction Pattern of Coal Slag

Figure C-3

X-ray Diffraction Pattern of Crushed Glass

Figure C-4

X-ray Diffraction Pattern of Garnet

Figure C-5

X-ray Diffraction Pattern of Specular Hematite

Figure C-6

Schematic of the Aerosol Generation and Delivery System in the Two-week and 39-week Inhalation Studies of Blasting Sand

Chamber concentrations shown are for the 2-week study.

Figure C-7

Schematic of the Aerosol Generation and Delivery System in the Two-week Inhalation Studies of Coal Slag and Garnet

Figure C-8

Schematic of the Aerosol Generation and Delivery System in the Two-week Inhalation Study of Crushed Glass

Figure C-9

Schematic of the Aerosol Generation and Delivery System in the Two-week Inhalation Study of Specular Hematite

Figure C-10

Schematic of the Aerosol Generation and Delivery System in the 39-week Inhalation Study of Specular Hematite