# Appendix B Tissue Burden Results

## B.1 Lung Deposition and Clearance Equations Used in the Two-week Inhalation Studies of Abrasive Blasting Agents

Lung clearance rates for the abrasive blasting agents blasting sand, coal slag, crushed glass, garnet, or specular hematite were calculated using Equation (1):

Equation (1): A(t) = A_0_(e^−kt^)

where A_(t)_ is the lung burden (μg abrasive blasting agents) at time t (t = 21 days postexposure), A_0_ is the lung burden at t = 0 days postexposure (day 16), and k is the lung clearance rate constant (fraction cleared per day). Lung burdens for the specular hematite study were all control corrected.

Lung clearance half-lives in days (t_½_) were calculated from Equation (2), where ln2 is the Naperian logarithm of 2:

Equation (2): t_1/2_ = ln2/k

Deposition rates were calculated from lung abrasive blasting agent burdens using Equation (3). The lung burden and time at terminal euthanasia and the calculated lung clearance rate constant were used to solve for the deposition rate α (μg/day).

Equation (3): A(t) = (α/k)(1 − e^−kt^)

In Equation (3), A(t) is the lung burden (μg abrasive blasting agents) at time t [t = 16 days on study]; α is the amount of abrasive blasting agents deposited (μg/day); and k is the first-order clearance rate constant derived from Equation (1). Steady-state or equilibrium lung burdens (A_e_, μg abrasive blasting agents) were calculated according to Equation (4):

Equation (4): A_e_ = α/k

## B.2 Lung Deposition and Clearance Equations Used in the 39-week Inhalation Studies of Abrasive Blasting Agents

The lung burden model used for these studies assumed a zero-order (constant) deposition rate and a first-order (with respect to lung burden) clearance rate as shown in Equation (5):

Equation (5): L_(t)_ = (D/k)(1 − e^−kt^)

In Equation (5), L(t) is the retained abrasive blasting agents lung burden (μg/lung) at any time t (days on study); D is the deposition rate (μg/day); and k is the lung clearance rate constant (days^−1^). Equation (5) also contains a boundary condition that at t = 0, the mass of abrasive blasting agents in the lung is zero. Lung burdens for the specular hematite study were all control corrected.

This model was fit to the abrasive blasting agents’ lung burden data collected during the in-life part of the 39-week studies. The model was fit to the individual animal data from each exposure group using SAS PROCNLIN (SAS Institute Inc., Cary, NC). Due to the potential for more uncertainty with relatively higher lung burdens, several weighting schemes were investigated, including unweighted, 1/variance, 1/square root of the variance, and bounding permissible estimate of k to greater than zero. Review of the results suggested that 1/square root of the variance was the best choice, so all results are presented from model fits using this weighting.

This model fit provided direct estimates of D and k along with their standard errors for each exposure group. Parameters estimated by the model fit were used to calculate the lung clearance half-time (t_1/2_, days) and the theoretical steady-state lung burden (L_ss_, μg abrasive blasting agents) for each exposure group along with their standard errors using propagation of error techniques and Equations (6) and (7), respectively:

Equation (6): t_½_ = ln2/k

Equation (7): L_ss_ = D/k

The total lung dose (mg/lung) administered in each exposure group was calculated using Equation (8):

Equation (8): Total dose = 271 × D/1,000

In Equation (8), 271 is the total number of study days; D is the deposition rate (μg/day); and dividing by 1,000 converts units from μg to mg. Also determined for each exposure group was the total amount of abrasive blasting agents cleared from the lungs during the studies, calculated as the difference between the calculated dose and the calculated lung burden at study day 271. This was expressed as both an absolute value and as the percentage relative to the total dose.

## B.3 Lung Overload Evaluation Used in the 39-week Inhalation Studies of Abrasive Blasting Agents

Calculations were undertaken to investigate the possibility that lung overload may have occurred in one or more of the exposure groups during the 39-week studies. Calculated lung burdens were converted to the equivalent volume of the abrasive blasting agents and compared to the respective threshold volume required to reach overload.

Using Equation (9), the total volume (μm^3^) of abrasive blasting agents in the lungs for each day on study was calculated:

Equation (9): V_p_(t) = [10^−3^ × L(t)/p] × (10^12^)

In Equation (9), V_p_(t) is the volume of the retained lung burden in μm^3^ at any time t (days on study), L(t) is the calculated lung burden (converted to mg by multiplying by 10^−3^ mg/μg) at time t, p is the density of the abrasive blasting agents (4,990 mg/cm^3^ or 2,780 mg/cm^3^ for specular hematite or blasting sand, respectively), and the factor 10^12^ converts cm^3^ to μm^3^.

Through an iterative calculation using Equation (10), the ratios of the volume of retained abrasive blasting agents’ lung burden at time t [V_p_(t)] to the threshold volume required for the onset of lung overload (V*) were determined:

Equation (10): R(t) = V_p_(t)/V*

The calculated ratios were used to determine the time of onset of lung overload and the extent of overload achieved over the course of the studies. The time of onset of the overload condition (t*, days) was determined as the earliest time (days on study) for which R(t) > 1.0. The maximum value of the ratio (R_max_) was used to determine the extent of overload that occurred by the end of the study (day 271).

Table B-1 Lung Weights and Lung Burdens for Male F344/NTac Rats in the Two-week Inhalation Study of Blasting Sand

| Chamber Control | | 3 mg/m^3^ | 15 mg/m^3^ | 30 mg/m^3^
n | 5 | | 5 | 5 | 5
Absolute Lung Wt. (g)
Day 1 | | 0.59 ± 0.04 | 0.54 ± 0.01 | 0.55 ± 0.01 | 0.56 ± 0.02
Day 5 | | 0.70 ± 0.06 | 0.64 ± 0.03 | 0.58 ± 0.01 | 0.66 ± 0.02
Day 8 | | 0.78 ± 0.04 | 0.73 ± 0.01 | 0.68 ± 0.03 | 0.71 ± 0.04
Day 12 | | 0.77 ± 0.03 | 0.77 ± 0.01 | 0.91 ± 0.07 | 0.82 ± 0.05
Day 15 | | 0.76 ± 0.04 | 0.85 ± 0.04 | 0.81 ± 0.07 | 0.82 ± 0.06
Day 16 | | 0.94 ± 0.05 | 0.89 ± 0.07 | 0.93 ± 0.06 | 0.86 ± 0.05^a^
Day 37 | | 0.99 ± 0.04 | 1.12 ± 0.06 | 1.00 ± 0.04 | 1.03 ± 0.04
μg Si/g Lung
Day 1 | | 0.6 ± 0.0 | 6.9 ± 0.6** | 32.9 ± 0.8** | 68.2 ± 3.1**
Day 5 | | 0.6 ± 0.0 | 33.4 ± 1.1** | 156.5 ± 3.7** | 277.4 ± 10.0**
Day 8 | | 1.0 ± 0.3 | 28.0 ± 1.4** | 124.0 ± 8.7** | 245.3 ± 18.0**
Day 12 | | 0.7 ± 0.1 | 52.1 ± 3.0** | 210.8 ± 13.4** | 464.0 ± 27.6**
Day 15 | | 0.6 ± 0.0 | 43.1 ± 3.0** | 203.0 ± 19.6** | 401.9 ± 28.7**
Day 16 | | 0.7 ± 0.1 | 48.9 ± 2.8** | 228.9 ± 13.4** | 526.7 ± 24.9**^a^
Day 37 | | 0.8 ± 0.2 | 33.3 ± 4.0** | 136.9 ± 5.6** | 280.6 ± 23.1**
μg Si/Total Lung
Day 1 | | 0.4 ± 0.0 | 3.7 ± 0.3** | 18.2 ± 0.6** | 38.3 ± 1.7**
Day 5 | | 0.4 ± 0.0 | 21.4 ± 1.0** | 90.8 ± 3.4** | 183.9 ± 7.6**
Day 8 | | 0.8 ± 0.2 | 20.5 ± 0.8** | 83.1 ± 3.6** | 170.4 ± 5.2**
Day 12 | | 0.6 ± 0.1 | 40.2 ± 2.0** | 188.8 ± 5.0** | 377.0 ± 13.8**
Day 15 | | 0.5 ± 0.0 | 36.1 ± 1.4** | 159.3 ± 5.8** | 322.8 ± 5.7**
Day 16 | | 0.7 ± 0.1 | 43.3 ± 2.7** | 208.9 ± 5.8** | 444.8 ± 8.0**^a^
Day 37 | | 0.8 ± 0.2 | 36.9 ± 3.5** | 137.1 ± 6.2** | 285.2 ± 20.4**
μg Blasting Sand/g Lung
Day 1 | | 1.5 ± 0.0 | 17.5 ± 1.5** | 83.6 ± 2.1** | 173.0 ± 7.9**
Day 5 | | 1.5 ± 0.0 | 84.8 ± 2.7** | 397.3 ± 9.5** | 704.2 ± 25.3**
Day 8 | | 2.6 ± 0.6 | 71.2 ± 3.7** | 314.7 ± 22.2** | 622.6 ± 45.6**
Day 12 | | 1.8 ± 0.3 | 132.2 ± 7.6** | 535.1 ± 34.0** | 1,177.8 ± 70.1**
Day 15 | | 1.5 ± 0.0 | 109.5 ± 7.5** | 515.4 ± 49.7** | 1,020.1 ± 72.9**
Day 16 | | 1.8 ± 0.3 | 124.1 ± 7.1** | 581.0 ± 34.0** | 1,336.9 ± 63.1**^a^
Day 37 | | 2.0 ± 0.5 | 84.6 ± 10.1** | 347.5 ± 14.2** | 712.1 ± 58.6**
μg Blasting Sand/Total Lung
Day 1 | | 0.9 ± 0.1 | 9.4 ± 0.7** | 46.2 ± 1.6** | 97.1 ± 4.3**
Day 5 | | 1.0 ± 0.1 | 54.4 ± 2.5** | 230.4 ± 8.6** | 466.6 ± 19.3**
Day 8 | | 2.0 ± 0.6 | 52.0 ± 1.9** | 210.9 ± 9.2** | 432.6 ± 13.3**
Day 12 | | 1.4 ± 0.2 | 102.1 ± 5.2** | 479.1 ± 12.6** | 956.9 ± 35.0**
Day 15 | | 1.1 ± 0.1 | 91.7 ± 3.5** | 404.2 ± 14.7** | 819.3 ± 14.4**
Day 16 | | 1.7 ± 0.2 | 109.8 ± 7.0** | 530.2 ± 14.8** | 1,128.8 ± 20.4**^a^
Day 37 | | 2.0 ± 0.6 | 93.8 ± 8.9** | 347.9 ± 15.8** | 723.9 ± 51.8**
μg Blasting Sand/g Lung per mg Blasting Sand/m^3^
Day 1 | | NA | 5.8 ± 0.5 | 5.6 ± 0.1 | 5.8 ± 0.3
Day 5 | | NA | 28.3 ± 0.9 | 26.5 ± 0.6 | 23.5 ± 0.8
Day 8 | | NA | 23.7 ± 1.2 | 21.0 ± 1.5 | 20.8 ± 1.5
Day 12 | | NA | 44.1 ± 2.5 | 35.7 ± 2.3 | 39.3 ± 2.3
Day 15 | | NA | 36.5 ± 2.5 | 34.4 ± 3.3 | 34.0 ± 2.4
Day 16 | | NA | 41.4 ± 2.4 | 38.7 ± 2.3 | 44.6 ± 2.1^a^
Day 37 | | NA | 28.2 ± 3.4 | 23.2 ± 0.9 | 23.7 ± 2.0
μg Blasting Sand/Total Lung per mg Blasting Sand/m^3^
Day 1 | | NA | 3.1 ± 0.2 | 3.1 ± 0.1 | 3.2 ± 0.1
Day 5 | | NA | 18.1 ± 0.8 | 15.4 ± 0.6 | 15.6 ± 0.6
Day 8 | | NA | 17.3 ± 0.6 | 14.1 ± 0.6 | 14.4 ± 0.4
Day 12 | | NA | 34.0 ± 1.7 | 31.9 ± 0.8 | 31.9 ± 1.2
Day 15 | | NA | 30.6 ± 1.2 | 26.9 ± 1.0 | 27.3 ± 0.5
Day 16 | | NA | 36.6 ± 2.3 | 35.3 ± 1.0 | 37.6 ± 0.7^a^
Day 37 | | NA | 31.3 ± 3.0 | 23.2 ± 1.1 | 24.1 ± 1.7

** Significantly different (p ≤ 0.01) from the chamber control group by Shirley’s test.

Data are presented as mean ± standard error. Days 1, 5, 12, and 16 were after the daily exposure, days 8 and 15 were before the daily exposure, and day 37 was after 21 days of recovery. For values reported as below the limit of quantification, the values shown are the constant of half the limit of quantification. Statistical tests were performed only on data that were not exposure concentration normalized.

NA = not applicable.

^a^ n = 4.

Table B-2 Lymph Node Weights for Male F344/NTac Rats in the Two-week Inhalation Study of Blasting Sand

| Chamber Control | | 3 mg/m^3^ | 15 mg/m^3^ | 30 mg/m^3^
n | 5 | | 5 | 5 | 5
Bronchial Lymph Node (g)
Day 1 | | 0.010 ± 0.002 | 0.011 ± 0.003 | 0.013 ± 0.002 | 0.010 ± 0.001
Day 5 | | 0.017 ± 0.009 | 0.013 ± 0.001 | 0.007 ± 0.000 | 0.015 ± 0.002
Day 8 | | 0.012 ± 0.002 | 0.015 ± 0.003 | 0.012 ± 0.003 | 0.011 ± 0.002
Day 12 | | 0.011 ± 0.001 | 0.011 ± 0.001 | 0.017 ± 0.002 | 0.015 ± 0.004
Day 15 | | 0.018 ± 0.003 | 0.011 ± 0.001 | 0.011 ± 0.001 | 0.016 ± 0.005
Day 16 | | 0.016 ± 0.004 | 0.017 ± 0.004 | 0.017 ± 0.003 | 0.016 ± 0.004
Day 37 | | 0.017 ± 0.003 | 0.028 ± 0.004 | 0.018 ± 0.004 | 0.025 ± 0.005
Mediastinal Lymph Node (g)
Day 1 | | 0.037 ± 0.020 | 0.017 ± 0.002 | 0.019 ± 0.003 | 0.015 ± 0.003
Day 5 | | 0.022 ± 0.004 | 0.023 ± 0.004 | 0.024 ± 0.003 | 0.025 ± 0.005
Day 8 | | 0.026 ± 0.003 | 0.027 ± 0.003 | 0.025 ± 0.006 | 0.023 ± 0.003
Day 12 | | 0.039 ± 0.011 | 0.035 ± 0.005 | 0.032 ± 0.002 | 0.035 ± 0.006
Day 15 | | 0.035 ± 0.006 | 0.026 ± 0.006 | 0.029 ± 0.003 | 0.029 ± 0.004
Day 16 | | 0.045 ± 0.008 | 0.035 ± 0.003 | 0.038 ± 0.003 | 0.041 ± 0.005
Day 37 | | 0.052 ± 0.003 | 0.067 ± 0.009 | 0.057 ± 0.002 | 0.066 ± 0.004

Data are presented as mean ± standard error. Days 1, 5, 12, and 16 were after the daily exposure, days 8 and 15 were before the daily exposure, and day 37 was after 21 days of recovery. Differences from the chamber control group are not significant by Dunnett’s test.

Table B-3 Lung Deposition and Clearance Parameter Estimates for Male F344/NTac Rats in the Two-week Inhalation Study of Blasting Sand

Parameter | 3 mg/m^3^ | 15 mg/m^3^ | 30 mg/m^3^
k (days^−1^) | 0.007 | 0.020 | 0.021
t_1/2_ (days) | 93 | 35 | 33
α (μg blasting sand/total lung per day) | 7 | 39 | 83
A_e_ (μg blasting sand/total lung) | 975 | 1,933 | 3,931

Data are presented as group mean values.

k = first-order lung clearance rate constant; t_1/2_ = clearance half-life; α = deposition rate; A_e_ = steady-state lung burden.

Table B-4 Lung Weights and Lung Burdens for Male F344/NTac Rats in the Two-week Inhalation Study of Coal Slag

| Chamber Control | | 3 mg/m^3^ | 15 mg/m^3^ | 30 mg/m^3^
n | 5 | | 5 | 5 | 5
Absolute Lung Wt. (g)
Day 1 | | 0.56 ± 0.11 | 0.50 ± 0.02 | 0.56 ± 0.04 | 0.54 ± 0.04
Day 5 | | 0.64 ± 0.06 | 0.64 ± 0.04 | 0.68 ± 0.04 | 0.65 ± 0.04
Day 8 | | 0.84 ± 0.01 | 0.71 ± 0.05 | 0.75 ± 0.07 | 0.80 ± 0.10
Day 12 | | 0.77 ± 0.10 | 0.82 ± 0.05 | 0.85 ± 0.03 | 0.83 ± 0.08
Day 15 | | 0.89 ± 0.09 | 0.84 ± 0.04 | 0.94 ± 0.06 | 0.88 ± 0.04
Day 16 | | 0.73 ± 0.02 | 0.73 ± 0.04 | 0.79 ± 0.03 | 0.88 ± 0.06*
Day 37 | | 1.03 ± 0.04 | 1.01 ± 0.08 | 1.16 ± 0.05 | 1.20 ± 0.06
μg Si/g Lung
Day 1 | | 0.6 ± 0.0 | 0.9 ± 0.3 | 13.8 ± 1.5** | 30.9 ± 2.0**
Day 5 | | 0.6 ± 0.0 | 16.4 ± 0.7** | 69.5 ± 3.2** | 115.3 ± 5.6**
Day 8 | | 0.6 ± 0.0 | 13.8 ± 1.1** | 60.1 ± 5.0** | 91.4 ± 11.2**
Day 12 | | 0.6 ± 0.0 | 25.0 ± 1.5** | 112.4 ± 2.2** | 200.1 ± 15.2**
Day 15 | | 0.6 ± 0.0 | 21.8 ± 1.7** | 93.9 ± 7.9** | 176.0 ± 4.6**
Day 16 | | 0.6 ± 0.0 | 35.2 ± 2.1** | 146.7 ± 5.6** | 240.6 ± 14.4**
Day 37 | | 0.6 ± 0.0 | 18.5 ± 1.7** | 77.7 ± 4.2** | 142.4 ± 8.1**
μg Si/Total Lung
Day 1 | | 0.3 ± 0.1 | 0.4 ± 0.1 | 7.6 ± 0.8** | 16.3 ± 0.7**
Day 5 | | 0.4 ± 0.0 | 10.3 ± 0.2** | 46.9 ± 1.8** | 74.6 ± 2.1**
Day 8 | | 0.5 ± 0.1 | 9.5 ± 0.1** | 43.6 ± 0.9** | 69.7 ± 5.0**
Day 12 | | 0.5 ± 0.1 | 20.1 ± 0.4** | 94.9 ± 1.6** | 160.8 ± 3.3**
Day 15 | | 0.5 ± 0.1 | 18.2 ± 1.2** | 86.8 ± 2.2** | 155.0 ± 3.3**
Day 16 | | 0.4 ± 0.0 | 25.5 ± 0.8** | 115.1 ± 3.6** | 209.9 ± 9.3**
Day 37 | | 0.6 ± 0.0 | 18.3 ± 1.0** | 89.2 ± 1.3** | 169.5 ± 5.4**
μg Coal Slag/g Lung
Day 1 | | 2.8 ± 0.0 | 4.0 ± 1.2 | 63.4 ± 6.9** | 141.5 ± 9.0**
Day 5 | | 2.8 ± 0.0 | 75.0 ± 3.2** | 318.8 ± 14.8** | 529.0 ± 25.6**
Day 8 | | 2.8 ± 0.0 | 63.1 ± 5.0** | 275.7 ± 22.9** | 419.1 ± 51.3**
Day 12 | | 2.8 ± 0.0 | 114.7 ± 6.9** | 515.8 ± 10.0** | 917.9 ± 69.7**
Day 15 | | 2.8 ± 0.0 | 100.1 ± 7.6** | 430.7 ± 36.0** | 807.2 ± 21.0**
Day 16 | | 2.8 ± 0.0 | 161.7 ± 9.6** | 672.8 ± 25.9** | 1,103.6 ± 65.9**
Day 37 | | 2.8 ± 0.0 | 84.7 ± 7.8** | 356.6 ± 19.1** | 653.3 ± 37.1**
μg Coal Slag/Total Lung
Day 1 | | 1.5 ± 0.3 | 1.9 ± 0.6 | 34.9 ± 3.7** | 74.7 ± 3.3**
Day 5 | | 1.8 ± 0.2 | 47.4 ± 1.1** | 215.3 ± 8.2** | 342.2 ± 9.7**
Day 8 | | 2.3 ± 0.3 | 43.6 ± 0.5** | 199.9 ± 3.9** | 319.8 ± 22.7**
Day 12 | | 2.1 ± 0.3 | 92.2 ± 1.6** | 435.2 ± 7.5** | 737.6 ± 15.3**
Day 15 | | 2.5 ± 0.3 | 83.6 ± 5.5** | 398.0 ± 10.1** | 710.9 ± 15.1**
Day 16 | | 2.0 ± 0.1 | 116.9 ± 3.9** | 528.2 ± 16.4** | 962.8 ± 42.8**
Day 37 | | 2.8 ± 0.1 | 83.7 ± 4.8** | 409.4 ± 6.1** | 777.5 ± 24.7**
μg Coal Slag/g Lung per mg Coal Slag/m^3^
Day 1 | | NA | 1.3 ± 0.4 | 4.2 ± 0.5 | 4.7 ± 0.3
Day 5 | | NA | 25.0 ± 1.1 | 21.3 ± 1.0 | 17.6 ± 0.9
Day 8 | | NA | 21.0 ± 1.7 | 18.4 ± 1.5 | 14.0 ± 1.7
Day 12 | | NA | 38.2 ± 2.3 | 34.4 ± 0.7 | 30.6 ± 2.3
Day 15 | | NA | 33.4 ± 2.5 | 28.7 ± 2.4 | 26.9 ± 0.7
Day 16 | | NA | 53.9 ± 3.2 | 44.9 ± 1.7 | 36.8 ± 2.2
Day 37 | | NA | 28.2 ± 2.6 | 23.8 ± 1.3 | 21.8 ± 1.2
μg Coal Slag/Total Lung per mg Coal Slag/m^3^
Day 1 | | NA | 0.6 ± 0.2 | 2.3 ± 0.3 | 2.5 ± 0.1
Day 5 | | NA | 15.8 ± 0.4 | 14.4 ± 0.6 | 11.4 ± 0.3
Day 8 | | NA | 14.6 ± 0.2 | 13.3 ± 0.3 | 10.7 ± 0.8
Day 12 | | NA | 30.7 ± 0.5 | 29.0 ± 0.5 | 24.6 ± 0.5
Day 15 | | NA | 27.9 ± 1.8 | 26.5 ± 0.7 | 23.7 ± 0.5
Day 16 | | NA | 39.0 ± 1.3 | 35.2 ± 1.1 | 32.1 ± 1.4
Day 37 | | NA | 27.9 ± 1.6 | 27.3 ± 0.4 | 25.9 ± 0.8

** Significantly different (p ≤ 0.01) from the chamber control group by Shirley’s test.

Data are presented as mean ± standard error. Days 1, 5, 12, and 16 were after the daily exposure, days 8 and 15 were before the daily exposure, and day 37 was after 21 days of recovery. For values reported as below the limit of quantification, the values shown are the constant of half the limit of quantification. Statistical tests were performed only on data that were not exposure concentration normalized.

NA = not applicable.

Table B-5 Lymph Node Weights for Male F344/NTac Rats in the Two-week Inhalation Study of Coal Slag

| Chamber Control | | 3 mg/m^3^ | 15 mg/m^3^ | 30 mg/m^3^
n | 5 | | 5 | 5 | 5
Bronchial Lymph Node (g)
Day 1 | | 0.006 ± 0.002 | 0.004 ± 0.001 | 0.006 ± 0.001 | 0.004 ± 0.002
Day 5 | | 0.005 ± 0.002 | 0.006 ± 0.003 | 0.006 ± 0.003 | 0.006 ± 0.003
Day 8 | | 0.006 ± 0.003 | 0.006 ± 0.002 | 0.009 ± 0.004 | 0.006 ± 0.004
Day 12 | | 0.007 ± 0.002 | 0.009 ± 0.003 | 0.017 ± 0.011 | 0.009 ± 0.006
Day 15 | | 0.012 ± 0.003 | 0.013 ± 0.009 | 0.012 ± 0.005 | 0.010 ± 0.003
Day 16 | | 0.010 ± 0.003 | 0.012 ± 0.003 | 0.010 ± 0.004 | 0.016 ± 0.012
Day 37 | | 0.023 ± 0.002 | 0.025 ± 0.032 | 0.032 ± 0.019 | 0.035 ± 0.024
Mediastinal Lymph Node (g)
Day 1 | | 0.027 ± 0.009 | 0.029 ± 0.011 | 0.030 ± 0.006 | 0.031 ± 0.010
Day 5 | | 0.031 ± 0.004 | 0.032 ± 0.012 | 0.033 ± 0.007 | 0.031 ± 0.007
Day 8 | | 0.025 ± 0.007 | 0.038 ± 0.004 | 0.037 ± 0.003 | 0.039 ± 0.021
Day 12 | | 0.038 ± 0.002 | 0.041 ± 0.011 | 0.046 ± 0.010 | 0.051 ± 0.010
Day 15 | | 0.048 ± 0.010 | 0.046 ± 0.011 | 0.050 ± 0.018 | 0.045 ± 0.017
Day 16 | | 0.042 ± 0.009 | 0.035 ± 0.007 | 0.033 ± 0.006 | 0.039 ± 0.006
Day 37 | | 0.065 ± 0.022 | 0.065 ± 0.026 | 0.068 ± 0.026 | 0.076 ± 0.013

Data are presented as mean ± standard error. Days 1, 5, 12, and 16 were after the daily exposure, days 8 and 15 were before the daily exposure, and day 37 was after 21 days of recovery. Differences from the chamber control group are not significant by Dunnett’s test.

Table B-6 Lung Deposition and Clearance Parameter Estimates for Male F344/NTac Rats in the Two-week Inhalation Study of Coal Slag

Parameter | 3 mg/m^3^ | 15 mg/m^3^ | 30 mg/m^3^
k (days^−1^) | 0.016 | 0.012 | 0.010
t_1/2_ (days) | 44 | 57 | 68
α (μg coal slag/total lung per day) | 8 | 36 | 65
A_e_ (μg coal slag/total lung) | 524 | 2,986 | 6,419

Data are presented as group mean values.

k = first-order lung clearance rate constant; t_1/2_ = clearance half-life; α = deposition rate; A_e_ = steady-state lung burden.

Table B-7 Lung Weights and Lung Burdens for Male F344/NTac Rats in the Two-week Inhalation Study of Crushed Glass

| Chamber Control | | 3 mg/m^3^ | 15 mg/m^3^ | 30 mg/m^3^
n | 5 | | 5 | 5 | 5
Absolute Lung Wt. (g)
Day 1 | | 0.63 ± 0.06 | 0.52 ± 0.03 | 0.54 ± 0.03 | 0.50 ± 0.01
Day 5 | | 0.62 ± 0.02 | 0.64 ± 0.02 | 0.61 ± 0.01 | 0.61 ± 0.02
Day 8 | | 0.83 ± 0.04 | 0.72 ± 0.05 | 0.79 ± 0.06 | 0.70 ± 0.03
Day 12 | | 0.80 ± 0.04 | 0.81 ± 0.04 | 0.79 ± 0.02 | 0.80 ± 0.06
Day 15 | | 0.90 ± 0.08 | 0.89 ± 0.04 | 0.91 ± 0.06 | 0.92 ± 0.06
Day 16 | | 0.88 ± 0.04 | 0.92 ± 0.08 | 0.82 ± 0.02 | 0.86 ± 0.04
Day 37 | | 1.19 ± 0.07 | 1.20 ± 0.05 | 1.12 ± 0.06 | 1.04 ± 0.03
μg Si/g Lung
Day 1 | | 0.6 ± 0.0 | 1.6 ± 0.8 | 15.1 ± 1.0** | 34.7 ± 2.0**
Day 5 | | 0.6 ± 0.0 | 6.8 ± 0.4** | 54.1 ± 2.5** | 95.9 ± 3.2**
Day 8 | | 0.6 ± 0.0 | 8.7 ± 0.6** | 38.3 ± 3.4** | 82.6 ± 5.3**
Day 12 | | 0.6 ± 0.0 | 18.9 ± 0.8** | 90.2 ± 3.1** | 172.9 ± 9.3**
Day 15 | | 0.6 ± 0.0 | 13.2 ± 1.1** | 70.4 ± 2.5** | 126.4 ± 7.7**
Day 16 | | 0.6 ± 0.0 | 19.2 ± 1.9** | 108.2 ± 5.5** | 188.3 ± 14.5**
Day 37 | | 0.6 ± 0.0 | 3.1 ± 0.4** | 32.7 ± 1.9** | 62.8 ± 1.0**
μg Si/Total Lung
Day 1 | | 0.4 ± 0.0 | 0.9 ± 0.4 | 8.1 ± 0.5** | 17.5 ± 1.2**
Day 5 | | 0.4 ± 0.0 | 4.3 ± 0.3** | 33.0 ± 1.8** | 58.8 ± 3.1**
Day 8 | | 0.5 ± 0.0 | 6.2 ± 0.2** | 29.3 ± 0.7** | 57.3 ± 2.8**
Day 12 | | 0.5 ± 0.0 | 15.3 ± 0.8** | 71.3 ± 2.5** | 136.1 ± 3.8**
Day 15 | | 0.5 ± 0.1 | 11.6 ± 0.4** | 63.2 ± 2.7** | 114.4 ± 2.5**
Day 16 | | 0.5 ± 0.0 | 17.0 ± 0.9** | 88.5 ± 4.7** | 159.9 ± 7.5**
Day 37 | | 0.7 ± 0.0 | 3.7 ± 0.6** | 37.1 ± 4.0** | 65.3 ± 2.6**
μg Crushed Glass/g Lung
Day 1 | | 1.9 ± 0.0 | 5.1 ± 2.5 | 48.3 ± 3.2** | 111.2 ± 6.4**
Day 5 | | 1.9 ± 0.0 | 21.7 ± 1.3** | 173.3 ± 8.0** | 307.3 ± 10.3**
Day 8 | | 1.9 ± 0.0 | 27.7 ± 1.8** | 122.6 ± 10.8** | 264.9 ± 17.0**
Day 12 | | 1.9 ± 0.0 | 60.5 ± 2.7** | 289.0 ± 9.8** | 554.1 ± 29.8**
Day 15 | | 1.9 ± 0.0 | 42.4 ± 3.6** | 225.6 ± 8.1** | 405.2 ± 24.8**
Day 16 | | 1.9 ± 0.0 | 61.4 ± 6.2** | 346.9 ± 17.6** | 603.6 ± 46.3**
Day 37 | | 1.9 ± 0.0 | 9.9 ± 1.4** | 104.7 ± 6.1** | 201.3 ± 3.2**
μg Crushed Glass/Total Lung
Day 1 | | 1.2 ± 0.1 | 2.7 ± 1.4 | 26.0 ± 1.6** | 56.1 ± 4.0**
Day 5 | | 1.2 ± 0.0 | 13.8 ± 1.0** | 105.9 ± 5.6** | 188.6 ± 10.0**
Day 8 | | 1.6 ± 0.1 | 19.7 ± 0.6** | 93.9 ± 2.1** | 183.6 ± 9.0**
Day 12 | | 1.5 ± 0.1 | 49.0 ± 2.7** | 228.6 ± 7.9** | 436.2 ± 12.3**
Day 15 | | 1.7 ± 0.2 | 37.1 ± 1.2** | 202.6 ± 8.5** | 366.7 ± 8.1**
Day 16 | | 1.7 ± 0.1 | 54.6 ± 2.7** | 283.5 ± 15.1** | 512.5 ± 23.9**
Day 37 | | 2.3 ± 0.1 | 11.9 ± 1.9** | 118.8 ± 12.9** | 209.4 ± 8.4**
μg Crushed Glass/g Lung per mg Crushed Glass/m^3^
Day 1 | | NA | 1.7 ± 0.8 | 3.2 ± 0.2 | 3.7 ± 0.2
Day 5 | | NA | 7.2 ± 0.4 | 11.6 ± 0.5 | 10.2 ± 0.3
Day 8 | | NA | 9.3 ± 0.6 | 8.2 ± 0.7 | 8.8 ± 0.6
Day 12 | | NA | 20.2 ± 0.9 | 19.3 ± 0.7 | 18.5 ± 1.0
Day 15 | | NA | 14.1 ± 1.2 | 15.0 ± 0.5 | 13.5 ± 0.8
Day 16 | | NA | 20.5 ± 2.1 | 23.1 ± 1.2 | 20.1 ± 1.5
Day 37 | | NA | 3.3 ± 0.5 | 7.0 ± 0.4 | 6.7 ± 0.1
μg Crushed Glass/Total Lung per mg Crushed Glass/m^3^
Day 1 | | NA | 0.9 ± 0.5 | 1.7 ± 0.1 | 1.9 ± 0.1
Day 5 | | NA | 4.6 ± 0.3 | 7.1 ± 0.4 | 6.3 ± 0.3
Day 8 | | NA | 6.6 ± 0.2 | 6.3 ± 0.1 | 6.1 ± 0.3
Day 12 | | NA | 16.3 ± 0.9 | 15.2 ± 0.5 | 14.5 ± 0.4
Day 15 | | NA | 12.4 ± 0.4 | 13.5 ± 0.6 | 12.2 ± 0.3
Day 16 | | NA | 18.2 ± 0.9 | 18.9 ± 1.0 | 17.1 ± 0.8
Day 37 | | NA | 4.0 ± 0.7 | 7.9 ± 0.9 | 7.0 ± 0.3

** Significantly different (p ≤ 0.01) from the chamber control group by Shirley’s test.

Data are presented as mean ± standard error. Days 1, 5, 12, and 16 were after the daily exposure, days 8 and 15 were before the daily exposure, and day 37 was after 21 days of recovery. For values reported as below the limit of quantification, the values shown are the constant of half the limit of quantification. Statistical tests were performed only on data that were not exposure concentration normalized.

NA = not applicable.

Table B-8 Lymph Node Weights for Male F344/NTac Rats in the Two-week Inhalation Study of Crushed Glass

| Chamber Control | | 3 mg/m^3^ | 15 mg/m^3^ | 30 mg/m^3^
n | 5 | | 5 | 5 | 5
Bronchial Lymph Node (g)
Day 1 | | 0.015 ± 0.004 | 0.012 ± 0.005 | 0.010 ± 0.004 | 0.011 ± 0.004
Day 5 | | 0.011 ± 0.004 | 0.011 ± 0.002 | 0.012 ± 0.005 | 0.012 ± 0.006
Day 8 | | 0.016 ± 0.005 | 0.015 ± 0.005 | 0.014 ± 0.008 | 0.016 ± 0.006
Day 12 | | 0.014 ± 0.001 | 0.012 ± 0.007 | 0.019 ± 0.015 | 0.011 ± 0.002
Day 15 | | 0.012 ± 0.004 | 0.010 ± 0.006 | 0.014 ± 0.002 | 0.015 ± 0.006
Day 16 | | 0.018 ± 0.005 | 0.013 ± 0.005 | 0.013 ± 0.003 | 0.016 ± 0.005
Day 37 | | 0.023 ± 0.005 | 0.023 ± 0.004 | 0.018 ± 0.009 | 0.020 ± 0.005
Mediastinal Lymph Node (g)
Day 1 | | 0.023 ± 0.004 | 0.025 ± 0.003 | 0.021 ± 0.003 | 0.024 ± 0.005
Day 5 | | 0.023 ± 0.005 | 0.028 ± 0.003 | 0.027 ± 0.007 | 0.020 ± 0.004
Day 8 | | 0.025 ± 0.001 | 0.034 ± 0.004 | 0.029 ± 0.009 | 0.032 ± 0.009
Day 12 | | 0.030 ± 0.005 | 0.031 ± 0.008 | 0.026 ± 0.007 | 0.032 ± 0.005
Day 15 | | 0.037 ± 0.006 | 0.040 ± 0.009 | 0.039 ± 0.003 | 0.037 ± 0.007
Day 16 | | 0.030 ± 0.008 | 0.028 ± 0.002 | 0.032 ± 0.009 | 0.032 ± 0.010
Day 37 | | 0.056 ± 0.013 | 0.049 ± 0.006 | 0.061 ± 0.020 | 0.059 ± 0.008

Data are presented as mean ± standard error. Days 1, 5, 12, and 16 were after the daily exposure, days 8 and 15 were before the daily exposure, and day 37 was after 21 days of recovery. Differences from the chamber control group are not significant by the Dunnett test.

Table B-9 Lung Deposition and Clearance Parameter Estimates for Male F344/NTac Rats in the Two-week Inhalation Study of Crushed Glass

Parameter | 3 mg/m^3^ | 15 mg/m^3^ | 30 mg/m^3^
k (days^−1^) | 0.072 | 0.041 | 0.043
t_1/2_ (days) | 10 | 17 | 16
α (μg crushed glass/total lung per day) | 6 | 24 | 44
A_e_ (μg crushed glass/total lung) | 80 | 586 | 1,035

Data are presented as group mean values.

k = first-order lung clearance rate constant; t_1/2_ = clearance half-life; α = deposition rate; A_e_ = steady-state lung burden.

Table B-10 Lung Weights and Lung Burdens for Male F344/NTac Rats in the Two-week Inhalation Study of Garnet

| Chamber Control | 3 mg/m^3^ | 15 mg/m^3^ | 30 mg/m^3^
n | 5 | 5 | 5 | 5
Absolute Lung Wt. (g)
Day 1 | 0.53 ± 0.02 | 0.53 ± 0.02 | 0.56 ± 0.04 | 0.60 ± 0.02
Day 5 | 0.63 ± 0.03 | 0.59 ± 0.01 | 0.59 ± 0.02 | 0.63 ± 0.05
Day 8 | 0.72 ± 0.03 | 0.71 ± 0.04 | 0.78 ± 0.05 | 0.69 ± 0.04
Day 12 | 0.67 ± 0.03 | 0.74 ± 0.03 | 0.80 ± 0.06 | 0.77 ± 0.03
Day 15 | 0.75 ± 0.03 | 0.75 ± 0.04 | 0.82 ± 0.05 | 0.84 ± 0.03
Day 16 | 0.82 ± 0.05 | 0.81 ± 0.04 | 0.83 ± 0.02 | 0.84 ± 0.02
Day 37 | 1.42 ± 0.28 | 1.14 ± 0.07 | 1.31 ± 0.10 | 1.35 ± 0.07
μg Si/g Lung
Day 1 | 0.6 ± 0.0 | 2.6 ± 0.3** | 15.2 ± 1.2** | 26.2 ± 1.0**
Day 5 | 0.6 ± 0.0 | 15.0 ± 0.6** | 68.0 ± 3.5** | 115.7 ± 4.9**
Day 8 | 0.6 ± 0.0 | 10.5 ± 0.4** | 50.2 ± 2.6** | 100.9 ± 5.1**
Day 12 | 0.6 ± 0.0 | 25.3 ± 0.8** | 110.4 ± 8.0** | 204.7 ± 11.8**
Day 15 | 0.6 ± 0.0 | 20.1 ± 1.5** | 96.7 ± 2.6** | 168.2 ± 4.3**
Day 16 | 1.1 ± 0.5 | 26.7 ± 0.6** | 119.2 ± 7.7** | 213.8 ± 12.6**
Day 37 | 0.6 ± 0.0 | 12.6 ± 0.9** | 65.5 ± 5.7** | 113.6 ± 10.1**
μg Si/Total Lung
Day 1 | 0.3 ± 0.0 | 1.4 ± 0.1** | 8.3 ± 0.4** | 15.6 ± 0.5**
Day 5 | 0.4 ± 0.0 | 8.9 ± 0.4** | 40.1 ± 2.9** | 72.3 ± 3.7**
Day 8 | 0.4 ± 0.0 | 7.4 ± 0.3** | 38.5 ± 1.5** | 68.6 ± 2.6**
Day 12 | 0.4 ± 0.0 | 18.7 ± 0.2** | 86.9 ± 3.4** | 155.9 ± 6.8**
Day 15 | 0.5 ± 0.0 | 15.2 ± 1.6** | 78.3 ± 2.8** | 140.3 ± 5.6**
Day 16 | 0.8 ± 0.3 | 21.6 ± 0.9** | 99.1 ± 7.1** | 178.0 ± 8.5**
Day 37 | 0.9 ± 0.2 | 14.2 ± 0.6** | 84.2 ± 4.9** | 151.2 ± 9.8**
μg Garnet/g Lung
Day 1 | 3.6 ± 0.0 | 15.3 ± 1.6** | 91.0 ± 7.2** | 157.0 ± 5.7**
Day 5 | 3.6 ± 0.0 | 90.0 ± 3.6** | 406.9 ± 21.0** | 692.7 ± 29.4**
Day 8 | 3.6 ± 0.0 | 62.6 ± 2.3** | 300.3 ± 15.6** | 604.4 ± 30.3**
Day 12 | 3.6 ± 0.0 | 151.4 ± 4.7** | 660.8 ± 47.7** | 1,225.6 ± 70.4**
Day 15 | 3.6 ± 0.0 | 120.1 ± 8.9** | 579.0 ± 15.5** | 1,007.1 ± 25.7**
Day 16 | 6.6 ± 3.0 | 160.0 ± 3.3** | 713.9 ± 46.3** | 1,280.2 ± 75.6**
Day 37 | 3.6 ± 0.0 | 75.5 ± 5.2** | 392.5 ± 34.1** | 680.4 ± 60.4**
μg Garnet/Total Lung
Day 1 | 1.9 ± 0.1 | 8.1 ± 0.8** | 49.6 ± 2.4** | 93.4 ± 2.9**
Day 5 | 2.3 ± 0.1 | 53.4 ± 2.2** | 240.0 ± 17.5** | 432.8 ± 22.1**
Day 8 | 2.6 ± 0.1 | 44.0 ± 1.5** | 230.5 ± 8.8** | 411.0 ± 15.7**
Day 12 | 2.4 ± 0.1 | 111.7 ± 1.0** | 520.1 ± 20.4** | 933.5 ± 40.7**
Day 15 | 2.7 ± 0.1 | 90.8 ± 9.4** | 469.0 ± 16.9** | 840.4 ± 33.5**
Day 16 | 5.0 ± 2.0 | 129.5 ± 5.4** | 593.5 ± 42.6** | 1,065.8 ± 51.2**
Day 37 | 5.1 ± 1.0 | 85.0 ± 3.4** | 504.3 ± 29.5** | 905.3 ± 58.4**
μg Garnet/g Lung per mg Garnet/m^3^
Day 1 | NA | 5.1 ± 0.5 | 6.1 ± 0.5 | 5.2 ± 0.2
Day 5 | NA | 30.0 ± 1.2 | 27.1 ± 1.4 | 23.1 ± 1.0
Day 8 | NA | 20.9 ± 0.8 | 20.0 ± 1.0 | 20.2 ± 1.0
Day 12 | NA | 50.5 ± 1.6 | 44.1 ± 3.2 | 40.9 ± 2.4
Day 15 | NA | 40.0 ± 3.0 | 38.6 ± 1.0 | 33.6 ± 0.9
Day 16 | NA | 53.3 ± 1.1 | 47.6 ± 3.1 | 42.7 ± 2.5
Day 37 | NA | 25.2 ± 1.8 | 26.2 ± 2.3 | 22.7 ± 2.0
μg Garnet/Total Lung per mg Garnet/m^3^
Day 1 | NA | 2.7 ± 0.3 | 3.3 ± 0.2 | 3.1 ± 0.1
Day 5 | NA | 17.8 ± 0.8 | 16.0 ± 1.2 | 14.4 ± 0.7
Day 8 | NA | 14.7 ± 0.5 | 15.4 ± 0.6 | 13.7 ± 0.5
Day 12 | NA | 37.2 ± 0.3 | 34.7 ± 1.4 | 31.1 ± 1.4
Day 15 | NA | 30.3 ± 3.1 | 31.3 ± 1.1 | 28.0 ± 1.1
Day 16 | NA | 43.2 ± 1.8 | 39.6 ± 2.8 | 35.5 ± 1.7
Day 37 | NA | 28.3 ± 1.1 | 33.6 ± 2.0 | 30.2 ± 2.0

** Significantly different (p ≤ 0.01) from the chamber control group by Shirley’s test.

Data are presented as mean ± standard error. Days 1, 5, 12, and 16 were after the daily exposure, days 8 and 15 were before the daily exposure, and day 37 was after 21 days of recovery. For values reported as below the limit of quantification, the values shown are the constant of half the limit of quantification. Statistical tests were performed only on data that were not exposure concentration normalized.

NA = not applicable.

Table B-11 Lymph Node Weights for Male F344/NTac Rats in the Two-week Inhalation Study of Garnet

| Chamber Control | | 3 mg/m^3^ | 15 mg/m^3^ | 30 mg/m^3^
n | 5 | | 5 | 5 | 5
Bronchial Lymph Node (g)
Day 1 | | 0.009 ± 0.002 | 0.013 ± 0.002 | 0.011 ± 0.004 | 0.014 ± 0.005
Day 5 | | 0.012 ± 0.004 | 0.007 ± 0.003 | 0.007 ± 0.002 | 0.010 ± 0.002
Day 8 | | 0.013 ± 0.005 | 0.013 ± 0.004 | 0.010 ± 0.003 | 0.015 ± 0.002
Day 12 | | 0.008 ± 0.002 | 0.013 ± 0.005* | 0.011 ± 0.002 | 0.014 ± 0.002*
Day 15 | | 0.011 ± 0.005 | 0.016 ± 0.004 | 0.013 ± 0.002 | 0.016 ± 0.003
Day 16 | | 0.012 ± 0.003 | 0.017 ± 0.009 | 0.021 ± 0.008 | 0.013 ± 0.004
Day 37 | | 0.015 ± 0.006 | 0.016 ± 0.006 | 0.024 ± 0.012 | 0.025 ± 0.014
Mediastinal Lymph Node (g)
Day 1 | | 0.015 ± 0.006 | 0.017 ± 0.006 | 0.018 ± 0.006 | 0.017 ± 0.002
Day 5 | | 0.020 ± 0.009 | 0.019 ± 0.013 | 0.015 ± 0.007 | 0.017 ± 0.005
Day 8 | | 0.030 ± 0.007 | 0.024 ± 0.007 | 0.028 ± 0.008 | 0.028 ± 0.006
Day 12 | | 0.037 ± 0.004 | 0.031 ± 0.005 | 0.034 ± 0.008 | 0.029 ± 0.007
Day 15 | | 0.038 ± 0.006 | 0.043 ± 0.007 | 0.044 ± 0.004 | 0.044 ± 0.004
Day 16 | | 0.052 ± 0.014 | 0.056 ± 0.013 | 0.051 ± 0.015 | 0.042 ± 0.017
Day 37 | | 0.055 ± 0.008 | 0.053 ± 0.003 | 0.062 ± 0.014 | 0.063 ± 0.006

* Significantly different (p ≤ .0.05) from the chamber control group by Dunnett’s test.

Data are presented as mean ± standard error. Days 1, 5, 12, and 16 were after the daily exposure, days 8 and 15 were before the daily exposure, and day 37 was after 21 days of recovery.

Table B-12 Lung Deposition and Clearance Parameter Estimates for Male F344/NTac Rats in the Two-week Inhalation Study of Garnet

Parameter | 3 mg/m^3^ | 15 mg/m^3^ | 30 mg/m^3^
k (days^−1^) | 0.020 | 0.008 | 0.008
t_1/2_ (days) | 35 | 90 | 89
α (μg garnet/total lung per day) | 9 | 39 | 71
A_e_ (μg garnet/total lung) | 474 | 5,089 | 9,089

Data are presented as group mean values.

k = first-order lung clearance rate constant; t_1/2_ = clearance half-life; α = deposition rate; A_e_ = steady-state lung burden.

Table B-13 Lung Weights and Lung Burdens for Male F344/NTac Rats in the Two-week Inhalation Study of Specular Hematite

| Chamber Control | 3 mg/m^3^ | 15 mg/m^3^ | 30 mg/m^3^ | 60 mg/m^3^
n | 5 | 5 | 5 | 5 | 5
Absolute Lung Wt. (g)
Day 1 | 0.57 ± 0.03 | 0.56 ± 0.03 | 0.58 ± 0.02 | 0.54 ± 0.02 | 0.54 ± 0.02
Day 5 | 0.66 ± 0.05 | 0.63 ± 0.02 | 0.64 ± 0.06 | 0.68 ± 0.04 | 0.60 ± 0.03
Day 8 | 0.70 ± 0.03 | 0.74 ± 0.04 | 0.69 ± 0.05 | 0.73 ± 0.05 | 0.74 ± 0.07
Day 12 | 0.83 ± 0.06 | 0.85 ± 0.09 | 0.72 ± 0.02 | 0.80 ± 0.05 | 0.81 ± 0.06
Day 15 | 0.79 ± 0.03 | 0.74 ± 0.03 | 0.81 ± 0.04 | 0.75 ± 0.04 | 0.87 ± 0.06
Day 16 | 0.81 ± 0.04 | 0.78 ± 0.02 | 0.87 ± 0.04 | 0.83 ± 0.11 | 0.79 ± 0.04
Day 37 | 0.95 ± 0.04 | 1.03 ± 0.07 | 1.01 ± 0.03 | 1.08 ± 0.02 | 1.52 ± 0.40*
μg Fe/g Lung
Day 1 | 48.82 ± 1.32 | 67.13 ± 3.62** | 134.02 ± 8.21** | 144.88 ± 4.69** | 238.41 ± 7.83**
Day 5 | 55.22 ± 2.45 | 124.91 ± 4.50** | 362.65 ± 35.17** | 504.46 ± 28.72** | 916.49 ± 43.84**
Day 8 | 54.50 ± 4.26 | 106.30 ± 4.83** | 326.25 ± 17.90** | 423.97 ± 27.71** | 709.69 ± 76.78**
Day 12 | 54.37 ± 0.59 | 141.68 ± 9.91** | 503.76 ± 14.31** | 797.62 ± 68.57** | 1,353.0 ± 68.74**
Day 15 | 64.17 ± 5.51 | 140.80 ± 4.96** | 432.67 ± 27.70** | 745.63 ± 28.70** | 1,264.5 ± 75.81**
Day 16 | 54.12 ± 2.99 | 157.68 ± 4.34** | 513.81 ± 17.19** | 835.34 ± 50.01** | 1,637.9 ± 87.70**
Day 37 | 68.66 ± 2.24 | 127.31 ± 4.04** | 309.93 ± 13.55** | 506.94 ± 19.01** | 797.55 ± 142.71**
μg Fe/g Lung (Control Corrected)
Day 1 | NA | 18.313 ± 3.619 | 85.200 ± 8.215 | 96.058 ± 4.693 | 189.589 ± 7.828
Day 5 | NA | 69.682 ± 4.497 | 307.429 ± 35.173 | 449.239 ± 28.720 | 861.263 ± 43.842
Day 8 | NA | 51.801 ± 4.826 | 271.749 ± 17.904 | 369.476 ± 27.714 | 655.194 ± 76.776
Day 12 | NA | 87.312 ± 9.908 | 449.385 ± 14.308 | 743.244 ± 68.574 | 1,298.65 ± 68.741
Day 15 | NA | 76.628 ± 4.960 | 368.499 ± 27.700 | 681.460 ± 28.705 | 1,200.33 ± 75.805
Day 16 | NA | 103.558 ± 4.339 | 459.688 ± 17.189 | 781.225 ± 50.009 | 1,583.73 ± 87.702
Day 37 | NA | 58.654 ± 4.041 | 241.275 ± 13.552 | 438.280 ± 19.014 | 728.890 ± 142.711
μg Fe/Total Lung (Control Corrected)
Day 1 | NA | 9.951 ± 1.714 | 48.450 ± 2.935 | 51.263 ± 2.529 | 101.681 ± 3.393
Day 5 | NA | 43.272 ± 1.878 | 189.985 ± 9.708 | 300.703 ± 6.666 | 514.595 ± 14.909
Day 8 | NA | 37.465 ± 2.154 | 184.982 ± 5.977 | 263.676 ± 9.185 | 465.181 ± 36.399
Day 12 | NA | 70.293 ± 1.164 | 322.883 ± 16.120 | 582.229 ± 28.068 | 1,040.18 ± 48.300
Day 15 | NA | 56.842 ± 3.567 | 294.985 ± 17.426 | 508.902 ± 7.167 | 1,030.47 ± 53.236
Day 16 | NA | 80.644 ± 3.755 | 396.829 ± 12.272 | 630.258 ± 33.507 | 1,235.45 ± 36.812
Day 37 | NA | 59.401 ± 3.259 | 245.654 ± 19.602 | 470.798 ± 16.954 | 890.235 ± 115.848
μg Specular Hematite/g Lung (Control Corrected)
Day 1 | NA | 26.388 ± 5.215 | 122.767 ± 11.837 | 138.412 ± 6.762 | 273.183 ± 11.280
Day 5 | NA | 100.406 ± 6.479 | 442.981 ± 50.681 | 647.319 ± 41.383 | 1,241.01 ± 63.173
Day 8 | NA | 74.642 ± 6.954 | 391.569 ± 25.799 | 532.386 ± 39.933 | 944.083 ± 110.628
Day 12 | NA | 125.810 ± 14.277 | 647.529 ± 20.617 | 1,070.96 ± 98.810 | 1,871.26 ± 99.051
Day 15 | NA | 110.415 ± 7.147 | 530.978 ± 39.913 | 981.930 ± 41.361 | 1,729.58 ± 109.230
Day 16 | NA | 149.219 ± 6.252 | 662.375 ± 24.767 | 1,125.68 ± 72.059 | 2,282.04 ± 126.372
Day 37 | NA | 84.516 ± 5.823 | 347.659 ± 19.527 | 631.528 ± 27.398 | 1,050.27 ± 205.635
μg Specular Hematite/Total Lung (Control Corrected)
Day 1 | NA | 14.339 ± 2.470 | 69.813 ± 4.228 | 73.866 ± 3.644 | 146.515 ± 4.889
Day 5 | NA | 62.352 ± 2.706 | 273.753 ± 13.989 | 433.290 ± 9.605 | 741.491 ± 21.482
Day 8 | NA | 53.984 ± 3.103 | 266.545 ± 8.612 | 379.937 ± 13.235 | 670.290 ± 52.448
Day 12 | NA | 101.287 ± 1.677 | 465.250 ± 23.229 | 838.947 ± 40.443 | 1,498.82 ± 69.597
Day 15 | NA | 81.905 ± 5.139 | 425.051 ± 25.110 | 733.288 ± 10.326 | 1,484.83 ± 76.708
Day 16 | NA | 116.202 ± 5.411 | 571.799 ± 17.683 | 908.153 ± 48.281 | 1,780.18 ± 53.043
Day 37 | NA | 85.591 ± 4.696 | 353.968 ± 28.245 | 678.383 ± 24.429 | 1,282.76 ± 166.928
μg Specular Hematite/Total Lung per mg Specular Hematite/m^3^ (Control Corrected)
Day 1 | NA | 4.780 ± 0.824 | 4.654 ± 0.282 | 2.462 ± 0.122 | 2.442 ± 0.081
Day 5 | NA | 20.784 ± 0.902 | 18.250 ± 0.933 | 14.443 ± 0.320 | 12.358 ± 0.358
Day 8 | NA | 17.995 ± 1.034 | 17.770 ± 0.574 | 12.665 ± 0.441 | 11.171 ± 0.874
Day 12 | NA | 33.763 ± 0.559 | 31.017 ± 1.549 | 27.965 ± 1.348 | 24.980 ± 1.160
Day 15 | NA | 27.302 ± 1.713 | 28.337 ± 1.674 | 24.443 ± 0.344 | 24.747 ± 1.279
Day 16 | NA | 38.734 ± 1.804 | 38.120 ± 1.179 | 30.272 ± 1.609 | 29.670 ± 0.884
Day 37 | NA | 28.531 ± 1.565 | 23.598 ± 1.883 | 22.613 ± 0.814 | 21.379 ± 2.782

* Significantly different (p ≤ 0.05) from the chamber control group by the Williams or Shirley tests.

** p ≤ 0.01.

Data are presented as mean ± standard error. Days 1, 5, 12, and 16 were after the daily exposure, days 8 and 15 were before the daily exposure, and day 37 was after 21 days of recovery. Statistical tests were performed only on data that were not control corrected.

NA = not applicable.

Table B-14 Lymph Node Weights for Male F344/NTac Rats in the Two-week Inhalation Study of Specular Hematite

| Chamber Control | 3 mg/m^3^ | 15 mg/m^3^ | 30 mg/m^3^ | 60 mg/m^3^
n | 5 | 5 | 5 | 5 | 5
Bronchial Lymph Node (g)
Day 1 | 0.017 ± 0.001 | 0.016 ± 0.003 | 0.018 ± 0.002 | 0.024 ± 0.003 | 0.021 ± 0.004
Day 5 | 0.010 ± 0.001 | 0.008 ± 0.001 | 0.009 ± 0.002 | 0.007 ± 0.002 | 0.008 ± 0.001
Day 8 | 0.020 ± 0.003 | 0.023 ± 0.003 | 0.022 ± 0.003 | 0.018 ± 0.002 | 0.025 ± 0.002
Day 12 | 0.031 ± 0.004 | 0.015 ± 0.003* | 0.023 ± 0.005 | 0.024 ± 0.003 | 0.022 ± 0.005
Day 15 | 0.015 ± 0.004 | 0.013 ± 0.002 | 0.012 ± 0.002 | 0.011 ± 0.001 | 0.016 ± 0.003
Day 16 | 0.018 ± 0.003 | 0.017 ± 0.002 | 0.015 ± 0.002 | 0.013 ± 0.001 | 0.012 ± 0.003
Day 37 | 0.019 ± 0.003 | 0.022 ± 0.010 | 0.033 ± 0.008 | 0.027 ± 0.003 | 0.036 ± 0.008
Mediastinal Lymph Node (g)
Day 1 | 0.025 ± 0.002 | 0.027 ± 0.002 | 0.029 ± 0.006 | 0.030 ± 0.002 | 0.031 ± 0.003
Day 5 | 0.026 ± 0.004 | 0.036 ± 0.003 | 0.028 ± 0.003 | 0.026 ± 0.005 | 0.032 ± 0.004
Day 8 | 0.038 ± 0.005 | 0.035 ± 0.002 | 0.038 ± 0.003 | 0.035 ± 0.004 | 0.035 ± 0.002
Day 12 | 0.027 ± 0.001 | 0.035 ± 0.002 | 0.030 ± 0.003 | 0.039 ± 0.003* | 0.028 ± 0.004
Day 15 | 0.037 ± 0.003 | 0.040 ± 0.007 | 0.042 ± 0.004 | 0.042 ± 0.004 | 0.045 ± 0.004
Day 16 | 0.029 ± 0.003 | 0.031 ± 0.002 | 0.033 ± 0.004 | 0.034 ± 0.005 | 0.030 ± 0.003
Day 37 | 0.056 ± 0.006 | 0.062 ± 0.008 | 0.057 ± 0.005 | 0.050 ± 0.003 | 0.063 ± 0.007

* Significantly different (p ≤ 0.05) from the chamber control group by Dunnett’s test.

Data are presented as mean ± standard error. Days 1, 5, 12, and 16 were after the daily exposure, days 8 and 15 were before the daily exposure, and day 37 was after 21 days of recovery.

Table B-15 Lung Deposition and Clearance Parameter Estimates for Male F344/NTac Rats in the Two-week Inhalation Study of Specular Hematite

Parameter | 3 mg/m^3^ | 15 mg/m^3^ | 30 mg/m^3^ | 60 mg/m^3^
k (days^−1^) | 0.015 | 0.023 | 0.014 | 0.016
t_1/2_ (days) | 48 | 30 | 50 | 44
α (μg specular hematite/total lung per day) | 8 | 43 | 63 | 126
A_e_ (μg specular hematite/total lung) | 559 | 1,868 | 4,557 | 8,057

Data are presented as group mean values.

k = first-order lung clearance rate constant; t_1/2_ = clearance half-life; α = deposition rate; A_e_ = steady-state lung burden.

Table B-16 Lung Weights and Lung Burdens for Male Sprague Dawley Rats in the 39-week Inhalation Study of Blasting Sand

| Chamber Control | 15 mg/m^3^ | 30 mg/m^3^ | 60 mg/m^3^
n | 5 | 5 | 5 | 5
Absolute Lung Wt. (g)
Week 1 | 0.93 ± 0.03 | 0.98 ± 0.03 | 0.99 ± 0.05 | 0.98 ± 0.02
Week 4 | 1.18 ± 0.04 | 1.27 ± 0.03 | 1.28 ± 0.04 | 1.30 ± 0.04
Week 8 | 1.34 ± 0.04 | 1.39 ± 0.04 | 1.39 ± 0.02 | 1.71 ± 0.05**
Week 16 | 1.40 ± 0.05 | 1.55 ± 0.05 | 1.66 ± 0.05** | 1.97 ± 0.07**
Week 26 | 1.48 ± 0.02 | 1.67 ± 0.05 | 1.92 ± 0.04** | 2.43 ± 0.15**
Week 39 | 1.63 ± 0.02 | 1.70 ± 0.04 | 1.96 ± 0.09* | 2.73 ± 0.16**
μg Si/g Lung
Week 1 | 0.6 ± 0.0 | 126.2 ± 6.3** | 237.4 ± 8.0** | 393.2 ± 24.5**
Week 4 | 0.6 ± 0.0 | 338.1 ± 6.4** | 697.9 ± 36.8** | 1,209.6 ± 54.3**
Week 8 | 0.6 ± 0.0 | 660.7 ± 25.1** | 1,182.3 ± 103.3** | 2,208.1 ± 130.6**
Week 16 | 0.6 ± 0.0 | 938.6 ± 74.2** | 2,093.6 ± 126.2** | 3,803.2 ± 141.8**
Week 26 | 0.6 ± 0.0 | 1,415.2 ± 96.3** | 3,023.4 ± 78.6** | 5,039.9 ± 105.6**
Week 39 | 0.6 ± 0.0 | 1,978.5 ± 81.9** | 3,773.5 ± 163.8** | 5,753.7 ± 224.2**
μg Si/Total Lung
Week 1 | 0.6 ± 0.0 | 124.5 ± 8.6** | 235.1 ± 13.0** | 387.8 ± 30.1**
Week 4 | 0.7 ± 0.0 | 428.7 ± 14.0** | 896.3 ± 55.2** | 1,575.5 ± 77.5**
Week 8 | 0.8 ± 0.0 | 916.2 ± 46.2** | 1,634.0 ± 132.2** | 3,766.0 ± 261.9**
Week 16 | 0.8 ± 0.0 | 1,461.0 ± 144.2** | 3,484.5 ± 276.7** | 7,486.0 ± 339.5**
Week 26 | 0.9 ± 0.0 | 2,356.7 ± 155.6** | 5,822.0 ± 247.5** | 12,230.5 ± 809.5**
Week 39 | 1.0 ± 0.0 | 3,376.5 ± 201.4** | 7,450.0 ± 663.3** | 15,643.5 ± 894.5**
μg Blasting Sand/g Lung
Week 1 | 1.5 ± 0.0 | 320.3 ± 15.9** | 602.5 ± 20.2** | 998.0 ± 62.3**
Week 4 | 1.5 ± 0.0 | 858.0 ± 16.3** | 1,771.2 ± 93.5** | 3,069.9 ± 137.8**
Week 8 | 1.5 ± 0.0 | 1,676.8 ± 63.6** | 3,000.9 ± 262.2** | 5,604.4 ± 331.4**
Week 16 | 1.5 ± 0.0 | 2,382.1 ± 188.4** | 5,313.7 ± 320.3** | 9,652.9 ± 359.8**
Week 26 | 1.5 ± 0.0 | 3,591.8 ± 244.4** | 7,673.6 ± 199.4** | 12,791.7 ± 268.0**
Week 39 | 1.5 ± 0.0 | 5,021.7 ± 207.9** | 9,577.4 ± 415.7** | 14,603.2 ± 569.1**
μg Blasting Sand/Total Lung
Week 1 | 1.4 ± 0.0 | 316.1 ± 21.9** | 596.8 ± 33.0** | 984.1 ± 76.5**
Week 4 | 1.8 ± 0.1 | 1,087.9 ± 35.5** | 2,274.9 ± 140.0** | 3,998.7 ± 196.7**
Week 8 | 2.0 ± 0.1 | 2,325.4 ± 117.4** | 4,147.1 ± 335.5** | 9,558.4 ± 664.7**
Week 16 | 2.1 ± 0.1 | 3,708.0 ± 366.0** | 8,843.9 ± 702.2** | 19,000.0 ± 861.8**
Week 26 | 2.2 ± 0.0 | 5,981.5 ± 395.0** | 14,776.6 ± 628.1** | 31,041.9 ± 2,054.5**
Week 39 | 2.5 ± 0.0 | 8,569.8 ± 511.2** | 18,908.6 ± 1,683.4** | 39,704.3 ± 2,270.3**
μg Blasting Sand/Total Lung per mg Blasting Sand/m^3^
Week 1 | NA | 21.1 ± 1.5 | 19.9 ± 1.1 | 16.4 ± 1.3
Week 4 | NA | 72.5 ± 2.4 | 75.8 ± 4.7 | 66.6 ± 3.3
Week 8 | NA | 155.0 ± 7.8 | 138.2 ± 11.2 | 159.3 ± 11.1
Week 16 | NA | 247.2 ± 24.4 | 294.8 ± 23.4 | 316.7 ± 14.4
Week 26 | NA | 398.8 ± 26.3 | 492.6 ± 20.9 | 517.4 ± 34.2
Week 39 | NA | 571.3 ± 34.1 | 630.3 ± 56.1 | 661.7 ± 37.8

* Significantly different (p ≤ 0.05) from the chamber control group by the Williams or Shirley tests.

** p ≤ 0.01.

Data are presented as mean ± standard error. For values reported as below the limit of quantification, the values shown are the constant of half the limit of quantification. Statistical tests were performed only on data that were not exposure concentration normalized.

NA = not applicable.

Table B-17 Bronchial Lymph Node Weights and Bronchial Lymph Node Burdens for Male Sprague Dawley Rats in the 39-week Inhalation Study of Blasting Sand

| Chamber Control | | 15 mg/m^3^ | 30 mg/m^3^ | 60 mg/m^3^
n | 5 | | 5 | 5 | 5
Absolute Bronchial Lymph Node Wt. (g)
Week 1 | | 0.012 ± 0.002 | 0.016 ± 0.005 | 0.016 ± 0.003 | 0.025 ± 0.003*
Week 4 | | 0.020 ± 0.002 | 0.025 ± 0.003 | 0.022 ± 0.001 | 0.037 ± 0.004**
Week 8 | | 0.023 ± 0.002 | 0.022 ± 0.004 | 0.026 ± 0.007 | 0.043 ± 0.007*
Week 16 | | 0.017 ± 0.002 | 0.029 ± 0.006 | 0.045 ± 0.006 | 0.101 ± 0.018**
Week 26 | | 0.018 ± 0.002 | 0.039 ± 0.005 | 0.077 ± 0.018** | 0.079 ± 0.008**
Week 39 | | 0.015 ± 0.002 | 0.115 ± 0.013 | 0.089 ± 0.019 | 0.193 ± 0.063**
μg Si/g Bronchial Lymph Node
Week 1 | | 0.6 ± 0.0 | 0.6 ± 0.0 | 20.4 ± 19.9 | 0.6 ± 0.0
Week 4 | | 0.6 ± 0.0 | 0.6 ± 0.0 | 0.6 ± 0.0 | 156.9 ± 63.0**
Week 8 | | 0.6 ± 0.0 | 250.0 ± 69.6* | 1,648.7 ± 462.4** | 4,023.1 ± 1,064.6**
Week 16 | | 0.6 ± 0.0 | 4,328.7 ± 1,340.9* | 12,851.2 ± 744.0** | 12,355.6 ± 863.2**
Week 26 | | 0.6 ± 0.0 | 10,247.9 ± 834.9** | 14,973.8 ± 1,845.7** | 17,755.9 ± 4,395.9**
Week 39 | | 0.6 ± 0.0 | 12,679.7 ± 1,598.5** | 21,846.3 ± 2,886.6** | 24,475.2 ± 4,539.0**
μg Si/Total Bronchial Lymph Node
Week 1 | | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.4 ± 0.4 | 0.0 ± 0.0
Week 4 | | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0 | 6.4 ± 2.7*
Week 8 | | 0.0 ± 0.0 | 5.3 ± 1.9** | 51.2 ± 22.0** | 187.9 ± 58.0**
Week 16 | | 0.0 ± 0.0 | 157.3 ± 55.8 | 580.0 ± 85.3** | 1,245.9 ± 252.3**
Week 26 | | 0.0 ± 0.0 | 401.3 ± 54.2** | 1,022.3 ± 84.7** | 1,481.4 ± 516.0**
Week 39 | | 0.0 ± 0.0 | 1,460.7 ± 236.8** | 1,767.6 ± 219.1** | 3,773.6 ± 709.4**
μg Blasting Sand/g Bronchial Lymph Node
Week 1 | | 1.4 ± 0.0 | 1.4 ± 0.0 | 51.9 ± 50.5 | 1.4 ± 0.0
Week 4 | | 1.4 ± 0.0 | 1.4 ± 0.0 | 1.4 ± 0.0 | 398.1 ± 159.9**
Week 8 | | 1.4 ± 0.0 | 634.5 ± 176.7* | 4,184.4 ± 1,173.5** | 10,210.9 ± 2,702.0**
Week 16 | | 1.4 ± 0.0 | 10,986.6 ± 3,403.4* | 32,617.2 ± 1,888.4** | 31,359.3 ± 2,190.9**
Week 26 | | 1.4 ± 0.0 | 26,009.9 ± 2,119.1** | 38,004.5 ± 4,684.4** | 45,065.9 ± 11,157.2**
Week 39 | | 1.4 ± 0.0 | 32,181.9 ± 4,057.1** | 55,447.4 ± 7,326.4** | 62,119.8 ± 11,520.4**
μg Blasting Sand/Total Bronchial Lymph Node
Week 1 | | 0.0 ± 0.0 | 0.0 ± 0.0 | 1.1 ± 1.1 | 0.0 ± 0.0
Week 4 | | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0 | 16.1 ± 6.8*
Week 8 | | 0.0 ± 0.0 | 13.3 ± 4.9** | 130.1 ± 55.8** | 476.8 ± 147.1**
Week 16 | | 0.0 ± 0.0 | 399.3 ± 141.6 | 1,472.0 ± 216.6** | 3,162.1 ± 640.3**
Week 26 | | 0.0 ± 0.0 | 1,018.5 ± 137.5** | 2,594.5 ± 214.9** | 3,759.8 ± 1,309.6**
Week 39 | | 0.0 ± 0.0 | 3,707.4 ± 601.0** | 4,486.3 ± 556.0** | 9,577.7 ± 1,800.5**
μg Blasting Sand/Total Bronchial Lymph Node per mg Blasting Sand/m^3^
Week 1 | | NA | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0
Week 4 | | NA | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.3 ± 0.1
Week 8 | | NA | 0.9 ± 0.3 | 4.3 ± 1.9 | 7.9 ± 2.5
Week 16 | | NA | 26.6 ± 9.4 | 49.1 ± 7.2 | 52.7 ± 10.7
Week 26 | | NA | 67.9 ± 9.2 | 86.5 ± 7.2 | 62.7 ± 21.8
Week 39 | | NA | 247.2 ± 40.1 | 149.5 ± 18.5 | 159.6 ± 30.0

* Significantly different (p ≤ 0.05) from the chamber control group by the Dunnett, Williams, Shirley, or Dunn tests.

** p ≤ 0.01.

Data are presented as mean ± standard error. For values reported as below the limit of quantification, the values shown are the constant of half the limit of quantification. Statistical tests were performed only on data that were not exposure concentration normalized.

NA = not applicable.

Table B-18 Mediastinal Lymph Node Weights and Mediastinal Lymph Node Burdens for Male Sprague Dawley Rats in the 39-week Inhalation Study of Blasting Sand

| Chamber Control | | 15 mg/m^3^ | 30 mg/m^3^ | 60 mg/m^3^
n | 5 | | 5 | 5 | 5
Absolute Mediastinal Lymph Node Wt. (g)
Week 1 | | 0.027 ± 0.003 | 0.034 ± 0.005 | 0.032 ± 0.005 | 0.032 ± 0.005
Week 4 | | 0.024 ± 0.004 | 0.032 ± 0.007 | 0.035 ± 0.005 | 0.033 ± 0.010
Week 8 | | 0.032 ± 0.006 | 0.040 ± 0.007 | 0.043 ± 0.008 | 0.053 ± 0.008
Week 16 | | 0.024 ± 0.004 | 0.031 ± 0.003 | 0.038 ± 0.007 | 0.046 ± 0.006*
Week 26 | | 0.030 ± 0.005 | 0.052 ± 0.007 | 0.075 ± 0.009 | 0.101 ± 0.037*
Week 39 | | 0.020 ± 0.001 | 0.034 ± 0.013 | 0.062 ± 0.017 | 0.072 ± 0.017*
μg Si/g Mediastinal Lymph Node
Week 1 | | 10.4 ± 9.9 | 0.6 ± 0.0 | 0.6 ± 0.0 | 0.6 ± 0.0
Week 4 | | 7.8 ± 7.2 | 0.6 ± 0.0 | 0.6 ± 0.0 | 114.3 ± 72.8
Week 8 | | 0.6 ± 0.0 | 130.7 ± 71.6 | 1,317.6 ± 616.8** | 2,728.4 ± 901.2**
Week 16 | | 59.8 ± 31.7 | 2,200.3 ± 834.3 | 4,117.0 ± 1,746.9* | 4,445.8 ± 1,964.6*
Week 26 | | 0.6 ± 0.0 | 9,272.0 ± 1,665.8** | 11,802.4 ± 1,061.5** | 12,320.0 ± 1,721.2**
Week 39 | | 13.2 ± 12.7 | 1,573.9 ± 1,124.5 | 14,494.7 ± 4,769.8* | 20,352.0 ± 6,432.3**
μg Si/total Mediastinal Lymph Node
Week 1 | | 0.3 ± 0.3 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0
Week 4 | | 0.3 ± 0.3 | 0.0 ± 0.0 | 0.0 ± 0.0 | 4.9 ± 3.2
Week 8 | | 0.0 ± 0.0 | 4.1 ± 1.8* | 54.8 ± 19.5* | 171.0 ± 79.1**
Week 16 | | 1.4 ± 0.6 | 73.1 ± 27.3 | 170.8 ± 91.2* | 218.7 ± 121.0**
Week 26 | | 0.0 ± 0.0 | 450.6 ± 72.0** | 888.4 ± 139.1** | 1,266.2 ± 461.2**
Week 39 | | 0.2 ± 0.2 | 105.8 ± 96.4 | 1,182.6 ± 456.9 | 1,767.0 ± 712.2**
μg Blasting Sand/g Mediastinal Lymph Node
Week 1 | | 26.5 ± 25.1 | 1.4 ± 0.0 | 1.4 ± 0.0 | 1.4 ± 0.0
Week 4 | | 19.8 ± 18.4 | 1.4 ± 0.0 | 1.4 ± 0.0 | 290.2 ± 184.8
Week 8 | | 1.4 ± 0.0 | 331.8 ± 181.7 | 3,344.2 ± 1,565.4** | 6,924.8 ± 2,287.3**
Week 16 | | 151.9 ± 80.5 | 5,584.4 ± 2,117.5 | 10,449.4 ± 4,433.7* | 11,283.8 ± 4,986.4*
Week 26 | | 1.4 ± 0.0 | 23,532.9 ± 4,227.8** | 29,955.5 ± 2,694.2** | 31,268.9 ± 4,368.6**
Week 39 | | 33.6 ± 32.2 | 3,994.6 ± 2,854.1 | 36,788.6 ± 12,106.2* | 51,654.8 ± 6,325.6**
μg Blasting Sand/Total Mediastinal Lymph Node
Week 1 | | 0.8 ± 0.7 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0
Week 4 | | 0.7 ± 0.7 | 0.0 ± 0.0 | 0.0 ± 0.0 | 12.4 ± 8.1
Week 8 | | 0.0 ± 0.0 | 10.5 ± 4.6* | 139.1 ± 49.6* | 434.0 ± 200.7**
Week 16 | | 3.5 ± 1.6 | 185.5 ± 69.4 | 433.6 ± 231.5* | 555.2 ± 307.0**
Week 26 | | 0.0 ± 0.0 | 1,143.7 ± 182.7** | 2,254.7 ± 352.9** | 3,213.7 ± 1,170.5**
Week 39 | | 0.6 ± 0.6 | 268.6 ± 244.7 | 3,001.6 ± 1,159.7 | 4,484.8 ± 1,807.7**
μg Blasting Sand/Total Mediastinal Lymph Node per mg Blasting Sand/m^3^
Week 1 | | NA | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0
Week 4 | | NA | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.2 ± 0.1
Week 8 | | NA | 0.7 ± 0.3 | 4.6 ± 1.7 | 7.2 ± 3.3
Week 16 | | NA | 12.4 ± 4.6 | 14.5 ± 7.7 | 9.3 ± 5.1
Week 26 | | NA | 76.2 ± 12.2 | 75.2 ± 11.8 | 53.6 ± 19.5
Week 39 | | NA | 17.9 ± 16.3 | 100.1 ± 38.7 | 74.7 ± 30.1

* Significantly different (p ≤ 0.05) from the chamber control group by the Williams or Shirley tests.

** p ≤ 0.01.

Data are presented as mean ± standard error. For values reported as below the limit of quantification, the values shown are the constant of half the limit of quantification. Statistical tests were performed only on data that were not exposure concentration normalized.

NA = not applicable.

Table B-19 Lung Deposition and Clearance Parameter Estimates for Male Sprague Dawley Rats in the 39-week Inhalation Study of Blasting Sand

Parameter | 15 mg/m^3^ | 30 mg/m^3^ | 60 mg/m^3^
k (days^−1^) | 0.003352 ± 0.000761 | 0.002556 ± 0.000841 | 0.000817 ± 0.000595
t_1/2_ (days) | 207 ± 47 | 271 ± 89 | 848 ± 618
D (μg blasting sand/total lung per day) | 45.67 ± 1.80 | 98.04 ± 5.14 | 171.98 ± 7.17
L_ss_ (μg blasting sand/total lung) | 13,624 ± 2,737 | 38,358 ± 11,090 | 210,387 ± 146,564

Data are presented as mean ± standard error.

k = first-order lung clearance rate constant; t_1/2_ = clearance half-life; D = deposition rate; L_ss_ = steady-state lung burden.

Table B-20 Lung Burden Overload Parameter Estimates for Male Sprague Dawley Rats in the 39-week Inhalation Study of Blasting Sand

Parameter | 15 mg/m^3^ | 30 mg/m^3^ | 60 mg/m^3^
t* = time of onset of overload condition [(R(t)>1.0] (days) | 137 | 55 | 30
L(t*) = lung burden at t* (mg blasting sand/lung) | 5.0 | 5.0 | 5.1
R_max_ = maximum R(t) at 271 days (unitless) | 1.6 | 3.8 | 8.4
Lung burden at R_max_ = L(t) at 271 days (mg blasting sand/lung) | 8.1 | 19.2 | 41.8
Total dose = deposited blasting sand at 271 days (mg/lung) | 12.4 | 26.6 | 46.6
Total blasting sand cleared = cleared blasting sand up through 271 days (mg/lung) | 4.2 | ^7.4^ | ^4.8^
% Total blasting sand cleared = (total blasting sand cleared/total dose) × 100 (unitless) | 34 | 28 | 10

R(t) = ratio of the volume of retained blasting sand lung burden at time t and the threshold volume required for the onset of lung overload.

Table B-21 Lung Weights and Lung Burdens for Male Sprague Dawley Rats in the 39-week Inhalation Study of Specular Hematite

| Chamber Control | 15 mg/m^3^ | 30 mg/m^3^ | 60 mg/m^3^
n | 5 | 5 | 5 | 5
Absolute Lung Wt. (g)
Week 1 | 0.93 ± 0.02 | 0.87 ± 0.01 | 0.91 ± 0.03 | 0.87 ± 0.03
Week 4 | 1.15 ± 0.03 | 1.16 ± 0.03 | 1.18 ± 0.04 | 1.17 ± 0.03
Week 8 | 1.30 ± 0.05 | 1.35 ± 0.06 | 1.36 ± 0.06 | 1.40 ± 0.03
Week 16 | 1.31 ± 0.04 | 1.44 ± 0.03* | 1.55 ± 0.04** | 1.56 ± 0.04**
Week 26 | 1.48 ± 0.04 | 1.52 ± 0.05 | 1.67 ± 0.04* | 1.96 ± 0.05**
Week 39 | 1.51 ± 0.07^a^ | 1.62 ± 0.03 | 1.76 ± 0.05** | 2.11 ± 0.05**^a^
μg Fe/g Lung
Week 1 | 49.16 ± 1.85 | 298.59 ± 20.00** | 519.56 ± 29.77** | 954.22 ± 35.07**
Week 4 | 63.41 ± 4.17 | 743.12 ± 25.15** | 1,342.6 ± 71.31** | 2,364.6 ± 104.08**
Week 8 | 70.11 ± 1.13 | 1,175.6 ± 102.53** | 2,044.0 ± 111.09** | 4,422.7 ± 113.60**
Week 16 | 82.04 ± 3.51 | 1,927.5 ± 197.10** | 3,915.1 ± 312.96** | 8,494.7 ± 383.33**
Week 26 | 85.84 ± 2.52 | 2,559.3 ± 315.11** | 5,338.8 ± 382.59** | 11,344 ± 467.86**
Week 39 | 95.50 ± 5.94^a^ | 3,501.4 ± 154.31* | 8,524.5 ± 567.31** | 16,136 ± 1,023.4**^a^
μg Fe/g Lung (Control Corrected)
Week 1 | NA | 249.428 ± 20.002 | 470.403 ± 29.771 | 905.059 ± 35.074
Week 4 | NA | 679.703 ± 25.154 | 1,279.13 ± 71.305 | 2,301.21 ± 104.078
Week 8 | NA | 1,105.53 ± 102.530 | 1,973.86 ± 111.092 | 4,352.62 ± 113.600
Week 16 | NA | 1,845.49 ± 197.093 | 3,833.07 ± 312.958 | 8,412.68 ± 383.334
Week 26 | NA | 2,473.47 ± 315.108 | 5,252.99 ± 382.587 | 11,257.7 ± 467.856
Week 39 | NA | 3,405.85 ± 154.306 | 8,429.03 ± 567.310 | 16,040.4 ± 1,023.37^a^
μg Fe/Total Lung (Control Corrected)
Week 1 | NA | 217.575 ± 18.963 | 427.885 ± 25.625 | 791.542 ± 48.353
Week 4 | NA | 790.089 ± 36.127 | 1,502.32 ± 72.776 | 2,686.73 ± 93.504
Week 8 | NA | 1,495.88 ± 183.505 | 2,702.75 ± 249.133 | 6,114.12 ± 238.881
Week 16 | NA | 2,663.99 ± 319.488 | 5,926.81 ± 462.104 | 13,162.7 ± 732.920
Week 26 | NA | 3,825.04 ± 581.773 | 8,811.78 ± 827.017 | 22,038.5 ± 1,110.46
Week 39 | NA | 5,521.67 ± 269.869 | 14,968.5 ± 1,412.83 | 33,923.6 ± 2,696.84^a^
μg Specular Hematite/g Lung (Control Corrected)
Week 1 | NA | 359.407 ± 28.822 | 677.814 ± 42.898 | 1,304.12 ± 50.539
Week 4 | NA | 979.400 ± 36.244 | 1,843.13 ± 102.746 | 3,315.86 ± 149.968
Week 8 | NA | 1,592.98 ± 147.737 | 2,844.17 ± 160.075 | 6,271.78 ± 163.688
Week 16 | NA | 2,659.20 ± 283.996 | 5,523.16 ± 450.948 | 12,122.0 ± 552.355
Week 26 | NA | 3,564.07 ± 454.045 | 7,569.15 ± 551.278 | 16,221.5 ± 674.145
Week 39 | NA | 4,907.56 ± 222.344 | 12,145.6 ± 817.449 | 23,113.0 ± 1,474.60^a^
μg Specular Hematite/Total Lung (Control Corrected)
Week 1 | NA | 313.509 ± 27.324 | 616.549 ± 36.924 | 1,140.55 ± 69.673
Week 4 | NA | 1,138.46 ± 52.056 | 2,164.73 ± 104.865 | 3,871.37 ± 134.732
Week 8 | NA | 2,155.44 ± 264.416 | 3,894.45 ± 358.981 | 8,809.97 ± 344.208
Week 16 | NA | 3,838.61 ± 460.357 | 8,540.07 ± 665.855 | 18,966.5 ± 1,056.08
Week 26 | NA | 5,511.59 ± 838.290 | 12,697.1 ± 1,191.67 | 31,755.7 ± 1,600.09
Week 39 | NA | 7,956.30 ± 388.860 | 21,568.5 ± 2,035.77 | 48,881.2 ± 3,885.94^a^
μg Specular Hematite/Total Lung per mg Specular Hematite/m^3^ (Control Corrected)
Week 1 | NA | 20.901 ± 1.822 | 20.552 ± 1.231 | 19.009 ± 1.161
Week 4 | NA | 75.897 ± 3.470 | 72.158 ± 3.495 | 64.523 ± 2.246
Week 8 | NA | 143.696 ± 17.628 | 129.815 ± 11.966 | 146.833 ± 5.737
Week 16 | NA | 255.907 ± 30.690 | 284.669 ± 22.195 | 316.108 ± 17.601
Week 26 | NA | 367.439 ± 55.886 | 423.236 ± 39.722 | 529.262 ± 26.668
Week 39 | NA | 530.420 ± 25.924 | 718.950 ± 67.859 | 814.687 ± 64.766^a^

* Significantly different (p ≤ 0.05) from the chamber control group by the Williams or Shirley tests.

** p ≤ 0.01.

Data are presented as mean ± standard error. Statistical tests were performed only on data that were not control corrected.

NA = not applicable.

^a^ n = 4.

Table B-22 Bronchial Lymph Node Weights and Bronchial Lymph Node Burdens for Male Sprague Dawley Rats in the 39-week Inhalation Study of Specular Hematite

| Chamber Control | | 15 mg/m^3^ | 30 mg/m^3^ | 60 mg/m^3^
n | 5 | | 5 | 5 | 5
Absolute Bronchial Lymph Node Wt. (g)
Week 1 | | 0.010 ± 0.002 | 0.011 ± 0.003 | 0.016 ± 0.003 | 0.011 ± 0.002
Week 4 | | 0.026 ± 0.005 | 0.010 ± 0.003 | 0.020 ± 0.006 | 0.021 ± 0.004
Week 8 | | 0.019 ± 0.003 | 0.020 ± 0.003 | 0.031 ± 0.004 | 0.028 ± 0.006
Week 16 | | 0.014 ± 0.003 | 0.015 ± 0.003 | 0.027 ± 0.004 | 0.036 ± 0.007**
Week 26 | | 0.013 ± 0.002 | 0.023 ± 0.005 | 0.040 ± 0.004** | 0.050 ± 0.006**
Week 39 | | 0.017 ± 0.006^a^ | 0.025 ± 0.005 | 0.041 ± 0.005 | 0.051 ± 0.014*^a^
μg Fe/Total Bronchial Lymph Node
Week 1 | | 0.245 ± 0.245 | 0.322 ± 0.171 | 0.405 ± 0.162 | 0.198 ± 0.112
Week 4 | | 0.943 ± 0.173 | 0.206 ± 0.206 | 1.255 ± 0.641 | 2.542 ± 0.641
Week 8 | | 0.954 ± 0.165 | 1.272 ± 0.417 | 17.879 ± 4.765** | 131.660 ± 35.090**
Week 16 | | 1.498 ± 0.320 | 46.721 ± 18.599** | 274.478 ± 118.208** | 737.400 ± 103.996**
Week 26 | | 1.713 ± 0.320 | 209.339 ± 112.024** | 1,532.45 ± 341.267** | 2,273.60 ± 397.628**
Week 39 | | 3.360 ± 1.198^a^ | 417.725 ± 102.586* | 2,227.05 ± 359.973** | 2,819.81 ± 1,232.548**^a^
μg Fe/Total Bronchial Lymph Node (Control Corrected)
Week 1 | | NA | 0.003 ± 0.001 | 0.146 ± 0.141 | 0.003 ± 0.001
Week 4 | | NA | 0.003 ± 0.001 | 0.541 ± 0.536 | 1.610 ± 0.634
Week 8 | | NA | 0.471 ± 0.305 | 16.925 ± 4.765 | 130.706 ± 35.090
Week 16 | | NA | 45.223 ± 18.599 | 272.980 ± 118.208 | 735.902 ± 103.996
Week 26 | | NA | 207.627 ± 112.024 | 1,530.74 ± 341.267 | 2,271.89 ± 397.628
Week 39 | | NA | 414.365 ± 102.586 | 2,223.69 ± 359.973 | 2,816.45 ± 1,232.54^a^
μg Fe/g Bronchial Lymph Node (Control Corrected)
Week 1 | | NA | 0.305 ± 0.000 | 7.109 ± 6.804 | 0.305 ± 0.000
Week 4 | | NA | 0.305 ± 0.000 | 13.736 ± 13.431 | 66.952 ± 23.086
Week 8 | | NA | 19.536 ± 12.140 | 512.937 ± 126.805 | 4,632.85 ± 1,399.06
Week 16 | | NA | 3,069.96 ± 1,345.72 | 9,608.73 ± 3,610.05 | 24,942.6 ± 5,803.36
Week 26 | | NA | 6,613.07 ± 2,849.64 | 3,7020.1 ± 6,164.50 | 44,022.6 ± 3,908.51
Week 39 | | NA | 19,295.5 ± 5,805.73 | 54,700.0 ± 6,555.39 | 48,099.2 ± 10,754.6^a^
μg Specular hematite/g bronchial lymph node (Control Corrected)
Week 1 | | NA | 0.440 ± 0.000 | 10.244 ± 9.804 | 0.440 ± 0.000
Week 4 | | NA | 0.440 ± 0.000 | 19.794 ± 19.354 | 96.473 ± 33.266
Week 8 | | NA | 28.151 ± 17.492 | 739.103 ± 182.716 | 6,675.57 ± 2,015.94
Week 16 | | NA | 4,423.58 ± 1,939.07 | 13,845.4 ± 5,201.81 | 35,940.3 ± 8,362.19
Week 26 | | NA | 9,528.92 ± 4,106.11 | 53,343.1 ± 8,882.56 | 63,433.2 ± 5,631.86
Week 39 | | NA | 27,803.3 ± 8,365.61 | 78,818.4 ± 9,445.80 | 69,307.2 ± 15,496.6^a^
μg Specular Hematite/Total Bronchial Lymph Node (Control Corrected)
Week 1 | | NA | 0.005 ± 0.001 | 0.210 ± 0.203 | 0.005 ± 0.001
Week 4 | | NA | 0.004 ± 0.002 | 0.779 ± 0.772 | 2.320 ± 0.913
Week 8 | | NA | 0.679 ± 0.439 | 24.387 ± 6.867 | 188.337 ± 50.562
Week 16 | | NA | 65.163 ± 26.800 | 393.343 ± 170.329 | 1,060.38 ± 149.850
Week 26 | | NA | 299.174 ± 161.418 | 2,205.67 ± 491.739 | 3,273.61 ± 572.951
Week 39 | | NA | 597.068 ± 147.818 | 3,204.16 ± 518.694 | 4,058.29 ± 1,775.99^a^
μg Specular hematite/total bronchial lymph node per mg specular hematite/m^3^ (Control Corrected)
Week 1 | | NA | 0.000 ± 0.000 | 0.007 ± 0.007 | 0.000 ± 0.000
Week 4 | | NA | 0.000 ± 0.000 | 0.026 ± 0.026 | 0.039 ± 0.015
Week 8 | | NA | 0.045 ± 0.029 | 0.813 ± 0.229 | 3.139 ± 0.843
Week 16 | | NA | 4.344 ± 1.787 | 13.111 ± 5.678 | 17.673 ± 2.498
Week 26 | | NA | 19.945 ± 10.761 | 73.522 ± 16.391 | 54.560 ± 9.549
Week 39 | | NA | 39.805 ± 9.855 | 106.805 ± 17.290 | 67.638 ± 29.600^a^

* Significantly different (p ≤ 0.05) from the chamber control group by the Williams or Shirley tests.

** p ≤ 0.01.

Data are presented as mean ± standard error. Statistical tests were performed only on data that were not control corrected. For values reported as below the limit of quantification, the values shown are the constant of half the limit of quantification.

NA = not applicable.

^a^ n = 4.

Table B-23 Mediastinal Lymph Node Weights and Mediastinal Lymph Node Burdens for Male Sprague Dawley Rats in the 39-week Inhalation Study of Specular Hematite

| Chamber Control | 15 mg/m^3^ | 30 mg/m^3^ | 60 mg/m^3^
n | 5 | 5 | 5 | 5
Absolute Mediastinal Lymph Node Wt. (g)
Week 1 | 0.018 ± 0.005 | 0.021 ± 0.003 | 0.026 ± 0.003 | 0.019 ± 0.001
Week 4 | 0.025 ± 0.003 | 0.024 ± 0.005 | 0.027 ± 0.005 | 0.023 ± 0.003
Week 8 | 0.025 ± 0.004 | 0.025 ± 0.002 | 0.026 ± 0.005 | 0.035 ± 0.008
Week 16 | 0.019 ± 0.002 | 0.020 ± 0.003 | 0.029 ± 0.004 | 0.034 ± 0.005*
Week 26 | 0.019 ± 0.004 | 0.032 ± 0.007 | 0.030 ± 0.002 | 0.046 ± 0.002**
Week 39 | 0.033 ± 0.009^a^ | 0.031 ± 0.011 | 0.031 ± 0.006 | 0.060 ± 0.011^a^
μg Fe/Total Mediastinal Lymph Node
Week 1 | 0.473 ± 0.473 | 0.893 ± 0.865 | 0.000 ± 0.000 | 0.128 ± 0.128
Week 4 | 0.194 ± 0.194 | 0.489 ± 0.489 | 0.139 ± 0.087 | 1.181 ± 0.490
Week 8 | 0.305 ± 0.222 | 0.041 ± 0.041 | 5.433 ± 3.848 | 193.108 ± 61.060**
Week 16 | 0.293 ± 0.265 | 41.371 ± 36.088 | 218.454 ± 75.099** | 925.510 ± 368.088**
Week 26 | 10.06 ± 9.11 | 155.20 ± 88.09 | 270.45 ± 145.34* | 952.30 ± 239.99**
Week 39 | 17.35 ± 9.88^a^ | 277.40 ± 119.71* | 554.53 ± 205.17** | 2,836.7 ± 873.64**^a^
μg Fe/Total Mediastinal Lymph Node (Control Corrected)
Week 1 | NA | 0.176 ± 0.028 | 0.219 ± 0.023 | 0.162 ± 0.008
Week 4 | NA | 0.207 ± 0.040 | 0.227 ± 0.046 | 0.192 ± 0.025
Week 8 | NA | 0.208 ± 0.021 | 4.186 ± 4.000 | 190.247 ± 62.967
Week 16 | NA | 41.337 ± 36.014 | 218.161 ± 75.099 | 925.040 ± 368.199
Week 26 | NA | 148.829 ± 86.492 | 260.829 ± 145.148 | 942.243 ± 239.989
Week 39 | NA | 260.049 ± 119.710 | 537.184 ± 205.170 | 2,819.34 ± 873.636^a^
μg Fe/g Mediastinal Lymph Node (Control Corrected)
Week 1 | NA | 8.500 ± 0.000 | 8.500 ± 0.000 | 8.500 ± 0.000
Week 4 | NA | 8.500 ± 0.000 | 8.500 ± 0.000 | 8.500 ± 0.000
Week 8 | NA | 8.500 ± 0.000 | 106.23 ± 97.736 | 5,156.3 ± 1,494.29
Week 16 | NA | 1,392.47 ± 1,150.63 | 6,673.66 ± 1,634.18 | 25,051.1 ± 11,041.0
Week 26 | NA | 5,032.76 ± 3,039.27 | 9,028.06 ± 5,037.73 | 20,818.0 ± 5,546.83
Week 39 | NA | 10,365.0 ± 4,741.15 | 15,503.4 ± 4,040.53 | 46,919.3 ± 14,649.1^a^
μg Specular Hematite/g Mediastinal Lymph Node (Control Corrected)
Week 1 | NA | 12.250 ± 0.000 | 12.250 ± 0.000 | 12.250 ± 0.000
Week 4 | NA | 12.250 ± 0.000 | 12.250 ± 0.000 | 12.250 ± 0.000
Week 8 | NA | 12.250 ± 0.000 | 153.079 ± 140.829 | 7,429.96 ± 2,153.16
Week 16 | NA | 2,006.44 ± 1,657.97 | 9,616.22 ± 2,354.72 | 36,096.7 ± 15,909.2
Week 26 | NA | 7,251.82 ± 4,379.35 | 13,008.7 ± 7,258.98 | 29,997.1 ± 7,992.56
Week 39 | NA | 14,935.1 ± 6,831.62 | 22,339.2 ± 5,822.09 | 67,607.0 ± 21,108.3^a^
μg Specular Hematite/Total Mediastinal Lymph Node (Control Corrected)
Week 1 | NA | 0.254 ± 0.040 | 0.316 ± 0.033 | 0.234 ± 0.011
Week 4 | NA | 0.298 ± 0.058 | 0.327 ± 0.067 | 0.276 ± 0.036
Week 8 | NA | 0.300 ± 0.030 | 6.032 ± 5.764 | 274.131 ± 90.730
Week 16 | NA | 59.564 ± 51.893 | 314.352 ± 108.212 | 1,332.91 ± 530.546
Week 26 | NA | 214.451 ± 124.628 | 375.834 ± 209.147 | 1,357.70 ± 345.805
Week 39 | NA | 374.711 ± 172.493 | 774.041 ± 295.633 | 4,062.45 ± 1,258.84^a^
μg Specular Hematite/Total Mediastinal Lymph node per mg Specular Hematite/m^3^ (Control Corrected)
Week 1 | NA | 0.017 ± 0.003 | 0.011 ± 0.001 | 0.004 ± 0.000
Week 4 | NA | 0.020 ± 0.004 | 0.011 ± 0.002 | 0.005 ± 0.001
Week 8 | NA | 0.020 ± 0.002 | 0.201 ± 0.192 | 4.569 ± 1.512
Week 16 | NA | 3.971 ± 3.460 | 10.478 ± 3.607 | 22.215 ± 8.842
Week 26 | NA | 14.297 ± 8.309 | 12.528 ± 6.972 | 22.628 ± 5.763
Week 39 | NA | 24.981 ± 11.500 | 25.801 ± 9.854 | 67.708 ± 20.981^a^

* Significantly different (p ≤ 0.05) from the chamber control group by the Dunnett, Williams, or Shirley tests.

** p ≤ 0.01.

Data are presented as mean ± standard error. Statistical tests were performed only on data that were not control corrected. For values reported as below the limit of quantification, the values shown are the constant of half the limit of quantification.

NA = not applicable.

^a^ n = 4.

Table B-24 Lung Deposition and Clearance Parameter Estimates for Male Sprague Dawley Rats in the 39-week Inhalation Study of Specular Hematite

Parameter | 15 mg/m^3^ | 30 mg/m^3^ | 60 mg/m^3^
k (days^−1^) | 0.00327 ± 0.00092 | −0.00004 ± 0.00086 | −0.00095 ± 0.00052
t_1/2_ (days) | 212 ± 59 | –^a^ | –
D (μg specular hematite/total lung per day) | 43.52 ± 3.79 | 76.34 ± 6.48 | 159.9 ± 8.1
L_ss_ (μg specular hematite/total lung) | 13,325 ± 2,705 | – | –

Data are presented as mean ± standard error.

k = first-order lung clearance rate constant; t_1/2_ = clearance half-life; D = deposition rate; L_ss_ = steady-state lung burden.

^a^ Resulting estimates are negative and so are not presented.

Table B-25 Lung Burden Overload Parameter Estimates for Male Sprague Dawley Rats in the 39-week Inhalation Study of Specular Hematite

Parameter | 15 mg/m^3^ | 30 mg/m^3^ | 60 mg/m^3^
t* = time of onset of overload condition [(R(t)>1.0] (days) | 344 | 118 | 55
L(t*) = lung burden at t* (mg specular hematite/lung) | 9.0 | 9.0 | 9.0
R_max_ = maximum R(t) at 271 days (unitless) | 0.9 | 2.3 | 5.5
Lung burden at R_max_ = L(t) at 271 days (mg specular hematite/lung) | 7.8 | 20.8 | 49.4
Total dose = deposited specular hematite at 271 days (mg/lung) | 11.8 | 20.7 | 43.3
Total specular hematite cleared = cleared specular hematite up through 271 days (mg/lung) | 4.0 | – | –
% Total specular hematite cleared = (total specular hematite cleared/total dose) × 100 (unitless) | 34 | – | –

R(t) = ratio of the volume of retained specular hematite lung burden at time t and the threshold volume required for the onset of lung overload. Resulting estimates are negative and so are not presented.