# Appendix A Bronchoalveolar Lavage Results

Table A-1 Bronchoalveolar Lavage Data for Sprague Dawley Rats in the 39-week Inhalation Study of Blasting Sand

| Chamber Control | 15 mg/m^3^ | 30 mg/m^3^ | 60 mg/m^3^
n | 8 | 8 | 8 | 8
Male
Viable Cells (%)
Week 4 | 90.53 ± 1.32 | 90.45 ± 1.89 | 94.75 ± 1.26* | 94.76 ± 0.70*
Week 16 | 70.20 ± 4.96 | 79.11 ± 4.31 | 77.96 ± 3.26 | 84.70 ± 2.26
Week 26 | 77.31 ± 2.77 | 87.55 ± 1.97* | 87.26 ± 2.08 | 87.00 ± 1.91
Week 39 | 93.44 ± 2.17 | 92.21 ± 2.94 | 95.85 ± 1.06 | 98.19 ± 0.27
Total Cells Counted
Week 4 | 248.8 ± 24.4 | 249.4 ± 23.2 | 280.6 ± 32.6 | 301.3 ± 30.6
Week 16 | 308 ± 67 | 413 ± 81 | 439 ± 73 | 502 ± 86
Week 26 | 186.3 ± 22.4 | 184.4 ± 28.7 | 262.5 ± 32.0 | 466.9 ± 52.4**
Week 39 | 128 ± 17 | 339 ± 65** | 450 ± 64** | 1,849 ± 301**
Macrophages (%)
Week 4 | 99.6 ± 0.2 | 99.6 ± 0.2 | 92.8 ± 2.1** | 61.9 ± 3.4**
Week 16 | 99.9 ± 0.1 | 75.5 ± 3.4** | 49.7 ± 2.9** | 51.2 ± 4.6**
Week 26 | 99.8 ± 0.1 | 69.9 ± 3.2** | 48.7 ± 4.9** | 33.3 ± 3.5**
Week 39 | 99.6 ± 0.2 | 57.0 ± 4.3** | 53.4 ± 4.8** | 43.6 ± 5.0**
Absolute Macrophages (#/μL)
Week 4 | 247.8 ± 24.5 | 248.5 ± 23.2 | 260.1 ± 29.1 | 182.5 ± 13.5
Week 16 | 307.8 ± 67.5 | 308.6 ± 60.7 | 216.5 ± 35.5 | 270.2 ± 56.9
Week 26 | 185.9 ± 22.4 | 131.0 ± 23.4 | 118.5 ± 7.5 | 148.9 ± 12.8
Week 39 | 127.6 ± 17.1 | 182.7 ± 29.0 | 238.0 ± 39.8* | 755.0 ± 88.4**
Lymphocytes (%)
Week 4 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.163 ± 0.125
Week 16 | 0.038 ± 0.038 | 0.238 ± 0.121 | 0.213 ± 0.113 | 1.125 ± 0.397**
Week 26 | 0.000 ± 0.000 | 0.513 ± 0.205 | 0.588 ± 0.163** | 1.138 ± 0.235**
Week 39 | 0.075 ± 0.049 | 0.613 ± 0.288 | 1.300 ± 0.306** | 0.713 ± 0.215
Absolute Lymphocytes (#/μL)
Week 4 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0388 ± 0.282
Week 16 | 0.100 ± 0.100 | 0.613 ± 0.361 | 1.013 ± 0.611 | 5.850 ± 2.092**
Week 26 | 0.000 ± 0.000 | 0.775 ± 0.291* | 1.625 ± 0.448** | 5.425 ± 1.350**
Week 39 | 0.113 ± 0.074 | 3.013 ± 1.943 | 5.663 ± 1.557** | 11.663 ± 3.723**
Neutrophils (%)
Week 4 | 0.450 ± 0.154 | 0.375 ± 0.209 | 7.250 ± 2.069** | 37.913 ± 3.405**
Week 16 | 0.075 ± 0.049 | 24.213 ± 3.419** | 50.125 ± 2.935** | 47.700 ± 4.788**
Week 26 | 0.200 ± 0.089 | 29.625 ± 3.159** | 50.750 ± 4.756** | 65.538 ± 3.461**
Week 39 | 0.325 ± 0.164 | 42.375 ± 4.191** | 45.288 ± 4.850** | 55.700 ± 4.975**
Absolute Neutrophils (#/μL)
Week 4 | 0.950 ± 0.271 | 0.850 ± 0.385 | 20.563 ± 7.392** | 118.463 ± 20.735**
Week 16 | 0.188 ± 0.123 | 102.963 ± 27.692** | 221.288 ± 42.081** | 255.875 ± 37.469**
Week 26 | 0.338 ± 0.129 | 52.588 ± 7.867** | 142.350 ± 27.283** | 312.600 ± 45.920**
Week 39 | 0.463 ± 0.221 | 153.113 ± 39.785** | 206.413 ± 38.182** | 1,082.09 ± 237.138**
Eosinophils (%)
Week 4 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 16 | 0.000 ± 0.000 | 0.075 ± 0.049 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 26 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 39 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Absolute Eosinophils (#/μL)
Week 4 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 16 | 0.000 ± 0.000 | 0.300 ± 0.237 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 26 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 39 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Basophils (%)
Week 4 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 16 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 26 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 39 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Absolute Basophils (#/μL)
Week 4 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 16 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 26 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 39 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Lactate Dehydrogenase (IU/L)
Week 4 | 34 ± 8 | 36 ± 4 | 40 ± 5 | 93 ± 7**
Week 16 | 31 ± 7 | 63 ± 6* | 104 ± 7** | 162 ± 16**
Week 26 | 36 ± 6 | 87 ± 7** | 160 ± 21** | 322 ± 26**
Week 39 | 19 ± 6 | 104 ± 29** | 144 ± 26** | 338 ± 24**
Albumin (g/dL)
Week 4 | 0.01 ± 0.01 | 0.01 ± 0.01 | 0.02 ± 0.01 | 0.02 ± 0.01
Week 16 | 0.02 ± 0.01 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Week 26 | 0.03 ± 0.01 | 0.03 ± 0.01 | 0.02 ± 0.01 | 0.03 ± 0.02
Week 39 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Female
Viable Cells (%)
Week 4 | 89.31 ± 1.66 | 90.10 ± 1.90 | 90.46 ± 0.66 | 91.35 ± 1.99
Week 26 | 86.49 ± 2.93 | 89.69 ± 2.20 | 90.00 ± 1.79 | 90.90 ± 1.83
Total Cells Counted
Week 4 | 446.9 ± 30.9 | 398.8 ± 24.2 | 403.1 ± 38.5 | 311.3 ± 24.6**
Week 26 | 294.4 ± 21.6 | 298.8 ± 31.4 | 592.5 ± 49.1** | 768.1 ± 30.3**
Macrophages (%)
Week 4 | 99.7 ± 0.1 | 99.8 ± 0.1 | 98.3 ± 0.5* | 72.2 ± 5.9**
Week 26 | 99.4 ± 0.3 | 53.1 ± 4.0** | 34.2 ± 3.5** | 27.3 ± 2.8**
Absolute Macrophages (#/μL)
Week 4 | 445.6 ± 31.1 | 397.9 ± 24.5 | 396.2 ± 37.5 | 222.1 ± 24.4**
Week 26 | 292.4 ± 21.0 | 158.1 ± 20.0** | 196.8 ± 17.9* | 207.7 ± 21.2
Lymphocytes (%)
Week 4 | 0.163 ± 0.091 | 0.038 ± 0.038 | 0.363 ± 0.082 | 0.650 ± 0.155**
Week 26 | 0.038 ± 0.038 | 0.250 ± 0.109 | 0.413 ± 0.091** | 0.200 ± 0.089
Absolute Lymphocytes (#/μL)
Week 4 | 0.650 ± 0.358 | 0.125 ± 0.125 | 1.575 ± 0.296* | 2.138 ± 0.523*
Week 26 | 0.138 ± 0.138 | 0.688 ± 0.271 | 2.538 ± 0.554** | 1.675 ± 0.734*
Neutrophils (%)
Week 4 | 0.150 ± 0.057 | 0.075 ± 0.049 | 0.963 ± 0.364 | 30.913 ± 5.685**
Week 26 | 0.538 ± 0.285 | 46.663 ± 4.075** | 65.363 ± 3.427** | 72.538 ± 2.769**
Absolute Neutrophils (#/μL)
Week 4 | 0.663 ± 0.256 | 0.325 ± 0.220 | 3.938 ± 1.834 | 92.838 ± 17.475**
Week 26 | 1.800 ± 0.962 | 139.988 ± 21.328** | 393.200 ± 46.620** | 558.775 ± 34.693**
Eosinophils (%)
Week 4 | 0.000 ± 0.000 | 0.125 ± 0.090 | 0.363 ± 0.240 | 0.375 ± 0.209
Week 26 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Absolute Eosinophils (#/μL)
Week 4 | 0.000 ± 0.000 | 0.413 ± 0.297 | 1.413 ± 0.964 | 1.250 ± 0.715
Week 26 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Basophils (%)
Week 4 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 26 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Absolute Basophils (#/μL)
Week 4 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 26 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Lactate Dehydrogenase (IU/L)
Week 4 | 34 ± 4 | 30 ± 2 | 37 ± 4 | 67 ± 11**
Week 26 | 26 ± 2 | 87 ± 12** | 235 ± 27** | 420 ± 20**
Albumin (g/dL)
Week 4 | 0.01 ± 0.01 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.01 ± 0.01
Week 26 | 0.06 ± 0.02 | 0.10 ± 0.01 | 0.07 ± 0.01 | 0.05 ± 0.01

* Significantly different (p ≤ 0.05) from the chamber control group by Dunn’s or Shirley’s test.

** p ≤ 0.01.

Data are presented as mean ± standard error.

Table A-2 Bronchoalveolar Lavage Data for Sprague Dawley Rats in the 39-week Inhalation Study of Specular Hematite

| Chamber Control | 15 mg/m^3^ | 30 mg/m^3^ | 60 mg/m^3^
Male
Week 4 | 8 | 8 | 8 | 8
Week 16 | 7 | 8 | 7 | 6
Week 26 | 8 | 8 | 8 | 8
Week 39 | 8 | 8 | 8 | 8
Viable Cells (%)
Week 4 | 81.76 ± 3.80 | 86.33 ± 3.33 | 87.74 ± 2.17 | 91.41 ± 1.67
Week 16 | 88.67 ± 0.52 | 91.03 ± 1.74 | 87.97 ± 1.91 | 92.95 ± 2.40
Week 26 | 93.03 ± 1.20 | 94.41 ± 1.26 | 98.19 ± 0.74** | 98.35 ± 0.60**
Week 39 | 89.75 ± 2.29 | 94.53 ± 1.82 | 97.35 ± 0.90* | 98.96 ± 0.39**
Total Cells Counted
Week 4 | 153.1 ± 22.1 | 198.1 ± 23.0 | 186.9 ± 24.0 | 155.6 ± 18.1
Week 16 | 554 ± 61 | 371 ± 42 | 313 ± 36** | 391 ± 28
Week 26 | 204.4 ± 18.9 | 192.5 ± 17.2 | 280.6 ± 27.6* | 608.1 ± 83.4**
Week 39 | 173 ± 11 | 273 ± 27* | 394 ± 51** | 749 ± 46**
Macrophages (%)
Week 4 | 99.7 ± 0.1 | 99.7 ± 0.2 | 99.2 ± 0.2 | 96.1 ± 0.8**
Week 16 | 99.7 ± 0.1 | 90.7 ± 2.1** | 78.6 ± 3.0** | 48.0 ± 3.6**
Week 26 | 99.9 ± 0.1 | 91.0 ± 1.8** | 73.7 ± 3.7** | 44.4 ± 2.4**
Week 39 | 99.8 ± 0.1 | 87.2 ± 2.4** | 65.1 ± 3.7** | 34.9 ± 4.3**
Absolute Macrophages (#/μL)
Week 4 | 152.6 ± 22.1 | 197.8 ± 23.2 | 185.3 ± 23.6 | 150.2 ± 18.6
Week 16 | 552.0 ± 60.9 | 334.8 ± 37.1* | 244.7 ± 30.4** | 188.5 ± 21.4**
Week 26 | 204.2 ± 19.0 | 173.7 ± 13.8 | 206.2 ± 22.5 | 273.4 ± 45.1
Week 39 | 172.8 ± 11.4 | 233.7 ± 18.2 | 252.0 ± 31.7 | 270.7 ± 44.3
Lymphocytes (%)
Week 4 | 0.200 ± 0.089 | 0.125 ± 0.125 | 0.413 ± 0.126 | 0.413 ± 0.126
Week 16 | 0.043 ± 0.043 | 0.838 ± 0.191** | 0.671 ± 0.148** | 1.733 ± 0.429**
Week 26 | 0.038 ± 0.038 | 0.000 ± 0.000 | 0.038 ± 0.038 | 0.038 ± 0.038
Week 39 | 0.000 ± 0.000 | 0.838 ± 0.328** | 1.463 ± 0.272** | 1.675 ± 0.351**
Absolute Lymphocytes (#/μL)
Week 4 | 0.288 ± 0.109 | 0.138 ± 0.138 | 0.838 ± 0.345 | 0.563 ± 0.148
Week 16 | 0.314 ± 0.314 | 3.150 ± 0.840* | 2.329 ± 0.637* | 6.350 ± 1.358**
Week 26 | 0.063 ± 0.063 | 0.000 ± 0.000 | 0.188 ± 0.188 | 0.263 ± 0.263
Week 39 | 0.000 ± 0.000 | 2.675 ± 1.281** | 5.500 ± 1.104** | 11.850 ± 2.142**
Neutrophils (%)
Week 4 | 0.125 ± 0.090 | 0.163 ± 0.091 | 0.375 ± 0.171 | 3.500 ± 0.721**
Week 16 | 0.286 ± 0.155 | 8.450 ± 1.943** | 20.743 ± 2.993** | 50.217 ± 3.741**
Week 26 | 0.088 ± 0.088 | 9.050 ± 1.772** | 26.313 ± 3.735** | 55.613 ± 2.385**
Week 39 | 0.188 ± 0.055 | 11.925 ± 2.173** | 33.550 ± 3.733** | 63.425 ± 4.085**
Absolute Neutrophils (#/μL)
Week 4 | 0.238 ± 0.169 | 0.200 ± 0.102 | 0.750 ± 0.351 | 4.900 ± 0.992**
Week 16 | 1.257 ± 0.647 | 32.700 ± 8.403** | 65.786 ± 13.558** | 195.767 ± 19.181**
Week 26 | 0.113 ± 0.113 | 18.788 ± 4.945** | 74.250 ± 12.106** | 334.488 ± 43.107**
Week 39 | 0.363 ± 0.112 | 36.175 ± 9.806** | 137.063 ± 32.091** | 466.263 ± 26.946**
Eosinophils (%)
Week 4 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 16 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.050 ± 0.050
Week 26 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 39 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Absolute Eosinophils (#/μL)
Week 4 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 16 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.250 ± 0.250
Week 26 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 39 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Basophils (%)
Week 4 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 16 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 26 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 39 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Absolute Basophils (#/μL)
Week 4 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 16 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 26 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 39 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Lactate Dehydrogenase (IU/L)
Week 4 | 22 ± 4 | 27 ± 5^a^ | 25 ± 7 | 30 ± 4
Week 16 | 38 ± 4^b^ | 64 ± 9* | 77 ± 8**^b^ | 263 ± 43**^b^
Week 26 | 14 ± 4^a^ | 31 ± 3** | 45 ± 3** | 126 ± 14**
Week 39 | 25 ± 2 | 43 ± 4** | 93 ± 6** | 219 ± 23**
Albumin (g/dL)
Week 4 | 0.01 ± 0.00 | 0.01 ± 0.01 | 0.01 ± 0.01 | 0.00 ± 0.00
Week 16 | 0.02 ± 0.01^b^ | 0.03 ± 0.01 | 0.01 ± 0.00^b^ | 0.02 ± 0.01^b^
Week 26 | 0.02 ± 0.01 | 0.03 ± 0.01 | 0.01 ± 0.00 | 0.02 ± 0.01
Week 39 | 0.02 ± 0.01 | 0.01 ± 0.01 | 0.01 ± 0.01 | 0.02 ± 0.01
Female
n | 8 | 8 | 8 | 8
Viable Cells (%)
Week 4 | 84.15 ± 3.63 | 82.81 ± 4.89 | 88.60 ± 1.84 | 90.39 ± 1.38
Week 26 | 93.45 ± 0.71 | 93.95 ± 1.38 | 94.66 ± 1.67 | 98.43 ± 0.36**
Total Cells Counted
Week 4 | 353.8 ± 32.0 | 337.5 ± 22.4 | 341.3 ± 16.6 | 268.8 ± 20.2
Week 26 | 248.1 ± 22.2 | 288.1 ± 15.2 | 490.0 ± 51.6** | 1,766.9 ± 95.1**
Macrophages (%)
Week 4 | 99.8 ± 0.1 | 99.4 ± 0.1 | 99.8 ± 0.1 | 96.0 ± 1.9*
Week 26 | 99.5 ± 0.2 | 92.2 ± 2.4** | 71.0 ± 2.6** | 30.0 ± 2.0**
Absolute Macrophages (#/μL)
Week 4 | 353.0 ± 31.8 | 335.6 ± 22.3 | 340.7 ± 16.6 | 257.6 ± 19.6*
Week 26 | 246.9 ± 22.1 | 264.1 ± 10.7 | 351.2 ± 42.3* | 525.6 ± 40.0**
Lymphocytes (%)
Week 4 | 0.000 ± 0.000 | 0.338 ± 0.115* | 0.163 ± 0.091 | 0.363 ± 0.158*
Week 26 | 0.038 ± 0.038 | 0.650 ± 0.197* | 1.575 ± 0.184** | 2.088 ± 0.391**
Absolute Lymphocytes (#/μL)
Week 4 | 0.000 ± 0.000 | 0.013 ± 0.339* | 0.588 ± 0.325 | 1.038 ± 0.499
Week 26 | 0.113 ± 0.113 | 1.975 ± 0.641* | 7.638 ± 1.125** | 38.475 ± 9.136**
Neutrophils (%)
Week 4 | 0.213 ± 0.113 | 0.250 ± 0.139 | 0.000 ± 0.000 | 3.650 ± 1.713
Week 26 | 0.450 ± 0.154 | 7.163 ± 2.181** | 27.463 ± 2.634** | 67.950 ± 1.916**
Absolute Neutrophils (#/μL)
Week 4 | 0.800 ± 0.467 | 0.888 ± 0.534 | 0.000 ± 0.000 | 10.138 ± 5.284
Week 26 | 1.163 ± 0.362 | 22.000 ± 7.745** | 131.175 ± 14.546** | 1,202.813 ± 77.715**
Eosinophils (%)
Week 4 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 26 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Absolute Eosinophils (#/μL)
Week 4 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 26 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Basophils (%)
Week 4 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 26 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Absolute Basophils (#/μL)
Week 4 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 26 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Lactate Dehydrogenase (IU/L)
Week 4 | 24 ± 2 | 24 ± 2 | 26 ± 4 | 35 ± 5
Week 26 | 14 ± 4 | 29 ± 4* | 71 ± 4** | 212 ± 17**
Albumin (g/dL)
Week 4 | 0.01 ± 0.00 | 0.02 ± 0.01 | 0.03 ± 0.01 | 0.06 ± 0.01**
Week 26 | 0.03 ± 0.01 | 0.05 ± 0.01 | 0.06 ± 0.01 | 0.05 ± 0.01

* Significantly different (p ≤ 0.05) from the chamber control group by Dunn’s or Shirley’s test.

** p ≤ 0.01.

Data are presented as mean ± standard error.

^a^ n = 7.

^b^ n = 8.

Table A-3 Comparisons of Selected Bronchoalveolar Lavage Data for Male Sprague Dawley Rats in the 39-week Inhalation Studies of Blasting Sand and Specular Hematite

| Concentration (mg/m^3^) | Blasting Sand^a^ | Specular Hematite | P Value^a^
Total Cells Counted
Week 4 | 0 | 248.75 ± 24.38 (8) | 153.13 ± 22.12 (8) | 0.173
| 15 | 249.38 ± 23.15 (8) | 198.13 ± 23.03 (8) | 0.645
| 30 | 280.63 ± 32.63 (8) | 186.88 ± 24.00 (8) | 0.234
| 60 | 301.25 ± 30.60 (8) | 155.63 ± 18.11 (8) | 0.029
Week 16 | 0 | 308.13 ± 67.41 (8) | 553.57 ± 60.62 (7) | 0.104
| 15 | 412.50 ± 81.10 (8) | 370.63 ± 41.63 (8) | 1.000
| 30 | 438.75 ± 72.76 (8) | 312.86 ± 36.35 (7) | 1.000
| 60 | 501.88 ± 85.76 (8) | 390.83 ± 28.03 (6) | 1.000
Week 26 | 0 | 186.25 ± 22.36 (8) | 204.38 ± 18.88 (8) | 1.000
| 15 | 184.38 ± 28.65 (8) | 192.50 ± 17.19 (8) | 1.000
| 30 | 262.50 ± 32.00 (8) | 280.63 ± 27.56 (8) | 1.000
| 60 | 466.88 ± 52.39 (8) | 608.13 ± 83.86 (8) | 0.983
Week 39 | 0 | 128.13 ± 17.14 (8) | 173.13 ± 11.41 (8) | 0.283
| 15 | 338.75 ± 64.98 (8) | 272.50 ± 27.37 (8) | 1.000
| 30 | 450.00 ± 63.84 (8) | 393.75 ± 51.33 (8) | 1.000
| 60 | 1,848.75 ± 300.88 (8) | 748.75 ± 45.84 (8) | 0.019
Lactate Dehydrogenase (IU/L)
Week 4 | 0 | 33.88 ± 8.26 (8) | 22.38 ± 3.71 (8) | 1.000
| 15 | 36.13 ± 4.42 (8) | 27.00 ± 4.50 (7) | 0.745
| 30 | 40.25 ± 5.03 (8) | 25.25 ± 7.13 (8) | 0.647
| 60 | 93.38 ± 6.69 (8) | 29.50 ± 3.86 (8) | 0.019
Week 16 | 0 | 30.75 ± 7.42 (8) | 39.71 ± 4.56 (7) | 1.000
| 15 | 63.25 ± 6.49 (8) | 64.13 ± 9.06 (8) | 1.000
| 30 | 104.00 ± 7.31 (8) | 78.43 ± 9.70 (7) | 0.406
| 60 | 162.00 ± 15.60 (8) | 250.33 ± 55.87 (6) | 1.000
Week 26 | 0 | 35.88 ± 5.94 (8) | 14.14 ± 3.78 (7) | 0.074
| 15 | 87.38 ± 7.24 (8) | 30.50 ± 2.88 (8) | 0.019
| 30 | 160.00 ± 20.95 (8) | 45.25 ± 3.02 (8) | 0.019
| 60 | 321.75 ± 26.34 (8) | 125.88 ± 14.30 (8) | 0.019
Week 39 | 0 | 18.88 ± 5.50 (8) | 25.00 ± 2.31 (8) | 0.590
| 15 | 103.50 ± 29.14 (8) | 42.50 ± 3.91 (8) | 0.646
| 30 | 143.63 ± 26.01 (8) | 92.75 ± 5.95 (8) | 0.707
| 60 | 338.25 ± 24.39 (8) | 219.25 ± 23.26 (8) | 0.069
Absolute Macrophages (#/μL)
Week 4 | 0 | 247.80 ± 24.48 (8) | 152.61 ± 22.08 (8) | 0.192
| 15 | 248.54 ± 23.22 (8) | 197.79 ± 23.19 (8) | 0.768
| 30 | 260.08 ± 29.13 (8) | 185.31 ± 23.61 98) | 0.415
| 60 | 182.45 ± 13.53 (8) | 150.18 ± 18.55 (8) | 0.707
Week 16 | 0 | 307.84 ± 67.45 (8) | 552.01 ± 60.90 (7) | 0.104
| 15 | 308.64 ± 60.67 (8) | 334.83 ± 37.14 (8) | 1.000
| 30 | 216.46 ± 35.54 (8) | 244.74 ± 30.36 (7) | 1.000
| 60 | 270.16 ± 56.87 (8) | 188.45 ± 21.42 (6) | 1.000
Week 26 | 0 | 185.92 ± 22.40 (8) | 204.21 ± 18.97 (8) | 1.000
| 15 | 131.02 ± 23.42 (8) | 173.73 ± 13.84 (8) | 0.284
| 30 | 118.54 ± 7.50 (8) | 206.21 ± 22.49 (8) | 0.029
| 60 | 148.86 ± 12.81 (8) | 273.40 ± 45.12 (8) | 0.069
Week 39 | 0 | 127.55 ± 17.06 (8) | 172.76 ± 11.38 (8) | 0.283
| 15 | 182.66 ± 29.01 (8) | 233.69 ± 18.19 (8) | 0.836
| 30 | 237.96 ± 39.77 (8) | 251.98 ± 31.65 (8) | 1.000
| 60 | 755.00 ± 88.39 (8) | 270.66 ± 44.33 (8) | 0.024
Absolute Neutrophils (#/μL)
Week 4 | 0 | 0.95 ± 0.27 (8) | 0.24 ± 0.17 (8) | 0.273
| 15 | 0.85 ± 0.39 (8) | 0.20 ± 0.10 (8) | 1.000
| 30 | 20.56 ± 7.39 (8) | 0.75 ± 0.35 (8) | 0.023
| 60 | 118.46 ± 20.74 (8) | 4.90 ± 0.99 (8) | 0.019
Week 16 | 0 | 0.19 ± 0.12 (8) | 1.26 ± 0.65 (7) | 1.000
| 15 | 102.95 ± 27.69 (8) | 32.70 ± 8.40 (8) | 0.157
| 30 | 221.28 ± 42.08 (8) | 65.79 ± 13.56 (7) | 0.042
| 60 | 225.87 ± 37.47 (8) | 195.77 ± 19.18 (6) | 1.000
Week 26 | 0 | 0.33 ± 0.13 (8) | 0.11 ± 0.11 (8) | 0.974
| 15 | 52.58 ± 7.86 (8) | 18.79 ± 4.95 (8) | 0.056
| 30 | 142.34 ± 27.28 (8) | 74.25 ± 12.11 (8) | 0.284
| 60 | 312.59 ± 45.91 (8) | 334.49 ± 43.02 (8) | 1.000
Week 39 | 0 | 0.47 ± 0.22 (8) | 0.36 ± 0.11 (8) | 1.000
| 15 | 153.10 ± 39.78 (8) | 36.18 ± 9.81 (8) | 0.069
| 30 | 206.39 ± 38.18 (8) | 137.06 ± 32.09 (8) | 0.415
| 60 | 1,082.08 ± 237.14 (8) | 466.26 ± 26.95 (8) | 0.128
Absolute Lymphocytes (#/μL)
Week 4 | 0 | 0.00 ± 0.00 (8) | 0.29 ± 0.11 (8) | 0.193
| 15 | 0.00 ± 0.00 (8) | 0.14 ± 0.14 (8) | 1.000
| 30 | 0.00 ± 0.00 (8) | 0.83 ± 0.34 (8) | 0.049
| 60 | 0.39 ± 0.28 (8) | 0.56 ± 0.15 (8) | 0.866
Week 16 | 0 | 0.10 ± 0.10 (8) | 0.31 ± 0.31 (7) | 1.000
| 15 | 0.61 ± 0.36 (8) | 3.15 ± 0.84 (8) | 0.120
| 30 | 1.01 ± 0.61 (8) | 2.33 ± 0.64 (7) | 0.466
| 60 | 5.84 ± 2.09 (8) | 6.35 ± 1.36 (6) | 1.000
Week 26 | 0 | 0.00 ± 0.00 (8) | 0.06 ± 0.06 (8) | 1.000
| 15 | 0.78 ± 0.29 (8) | 0.00 ± 0.00 (8) | 0.100
| 30 | 1.63 ± 0.45 (8) | 0.19 ± 0.19 (8) | 0.126
| 60 | 5.42 ± 1.35 (8) | 0.26 ± 0.26 (8) | 0.022
Week 39 | 0 | 0.11 ± 0.07 (8) | 0.00 ± 0.00 (8) | 0.764
| 15 | 2.99 ± 1.94 (8) | 2.68 ± 1.28 (8) | 1.000
| 30 | 5.65 ± 1.56 (8) | 5.50 ± 1.10 (8) | 1.000
| 60 | 11.67 ± 3.72 (8) | 11.85 ± 2.14 (8) | 1.000

Data are presented as mean ± standard error (n).

^a^ P values determined by the two-sided Wilcoxon rank-sum test with Bonferroni correction.