# Peer Review

The draft NTP Technical Report on the Toxicity Studies of 5-Amino-o-cresol (CASRN 2835-95-2) Administered Dermally to F344/NTac Rats and B6C3F1/N Mice was evaluated by the reviewers listed below. These reviewers served as independent scientists, not as representatives of any institution, company, or governmental agency. In this capacity, reviewers determined if the design and conditions of these NTP studies were appropriate and ensured that this NTP Toxicity Study Report presented the experimental results and conclusions fully and clearly.

## Peer Reviewers

- Donna F. Kusewitt, D.V.M., Ph.D.
  University of Texas
  Smithville, Texas, USA
- Lena A. Nylander-French, Ph.D.
  University of North Carolina at Chapel Hill
  Chapel Hill, North Carolina, USA