# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  J.K. Dunnick, Ph.D., Study Scientist
  C.R. Blystone, Ph.D.
  P.M. Foster, Ph.D.
  M.J. Hooth, Ph.D.
  A.P. King-Herbert, D.V.M.
  G.E. Kissling, Ph.D.
  D.E. Malarkey, D.V.M., Ph.D.
  B.S. McIntyre, Ph.D.
  J.M. Sanders, Ph.D.
  M.D. Stout, Ph.D.
  G.S. Travlos, D.V.M.
  M.K. Vallant, M.S., MT
  S. Waidyanatha, Ph.D.
  N.J. Walker, Ph.D.
  K.L. Witt, M.S.
- Battelle Columbus Operations, Columbus, Ohio, USA
  Conducted studies and evaluated pathology findings
  M.R. Hejtmancik, Ph.D., Principal Investigator
  C.A. Colleton, D.V.M.
  T.A. Peace, D.V.M.
- Experimental Pathology Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  A.E. Brix, D.V.M., Ph.D., Study Pathologist
- Conducted pathology review
  J.C. Peckham, D.V.M., Ph.D.
- ILS, Inc., Research Triangle Park, North Carolina, USA
  Coordinated NTP Pathology Working Group (February 14, 2008)
  S. Newbigging, D.V.M., D.V.Sc.
- Bridge Global Pharmaceutical Services, Inc., Gaithersburg, Maryland, USA
  Provided SMVCE analysis
  B.J.T. Muir, Ph.D., Principal Investigator
  B. Atkinson, M.Sc.
  Y. Wang, M.S.