# References

1 Hazardous Substances Data Bank (HSDB) entry for: 5-Amino-o-cresol. National Institutes for Occupational Safety and Health (NIOSH); 2012. http://toxnet.nlm.nih.gov/cgi-bin/sis/search2/r?dbs+hsdb:@term+@DOCNO+7152
2 Lewis R Sax’s dangerous properties of industrial materials. 10th ed. New York (NY): John Wiley and Sons, Inc; 1999.
3 United States Environmental Protection Agency (USEPA). Estimation Programs Interface Suite™ for Microsoft® Windows, v 3.10. Washington, DC: US Environmental Protection Agency; 2001.
4 Corbett JF An historical review of the use of dye precursors in the formulation of commercial oxidation hair dyes. Dyes Pigments. 1999; 41(1-2):127–136.http://dx.doi.org/10.1016/S0143-7208(98)00075-8
5 Cosmetic Ingredient Review Expert Panel Annual review of cosmetic ingredient safety assessments: 2005/2006. Int J Toxicol. 2008; 27 Suppl 1:77–142. http://dx.doi.org/10.1080/10915810802032362 18569164
6 Corbett JF Synthetic dyes for human hair. In: Freeman H Peters Aeditors. Colorants for non-textile applications. Amsterdam, Netherlands: Elsevier BV; 2000. p. 456–477.http://dx.doi.org/10.1016/B978-044482888-0/50041-6
7 Bureau of Labor Statistics (BLS). Quick facts: Barbers, hairdressers, and cosmetologists. Occupational Outlook Handbook, 2012-2013 ed. Washington, DC: United States Department of Labor; 2012. https://www.bls.gov/ooh/personal-care-and-service/barbers-hairdressers-and-cosmetologists.htm.
8 National Cancer Institute (NCI). Hair dyes and cancer risk. Bethesda, MD: National Institutes of Health; 2011. https://www.cancer.gov/cancertopics/factsheet/Risk/hair-dyes [Accessed: September 25, 2012]
9 Huncharek M Kupelnick B Personal use of hair dyes and the risk of bladder cancer: results of a meta-analysis. Public Health Rep. 2005; 120(1):31–38. http://dx.doi.org/10.1177/003335490512000107 15736329
10 National Institute for Occupational Safety and Health (NIOSH). National Occupational Exposure Survey (1981-1983) [unpublished provisional data]. Cincinnati, OH. 1990.
11 International Agency for Research on Cancer (IARC). IARC Monographs on the Evaluation of Carcinogenic Risks to Humans. Occupational exposures of hairdressers and barbers and personal use of hair colourants. Lyon, France: IARC; 2010.
12 Food and Drug Administation (FDA). Hair dye products. 1997. https://web.archive.org/web/20090609102656/http://www.fda.gov/cosmetics/productandingredientsafety/productinformation/ucm143066.htm [Accessed: September 28, 2012]
13 Akerson J Pohl S Varco J Wallace P Wolfram L Hair preparations. In: Kroschwitz J Howe-Grant Meditors. Kirk-Othmer Encyclopedia of Chemical Technology. 4th ed. New York (NY): John Wiley & Sons Inc; 1994. p. 881–918.
14 Code of Federal Regulations (CFR). 21:Part 73.
15 Code of Federal Regulations (CFR). 21:Part 74.
16 Meadows M Heading off hair-care disasters. Use caution with relaxers and dyes. FDA Consum. 2001; 35(1):21–24. 11930919
17 Konrad E, Mager H, Hoffmann A. inventors. Composition and method for the oxidative dyeing of hair. United States patent 4,883,656; 1989.
18 Hedtke B Gao Z Chen L-J Weber WM Dix KJ Metabolism and disposition of [14C]5-amino-o-cresol in female F344 rats and B6C3F1 mice. Xenobiotica. 2008; 38(2):171–184. http://dx.doi.org/10.1080/00498250701744666 18197558
19 Goebel C, Hewitt N, Kunze G, Wenker M, Hein D, Beck H, Skare J. Skin metabolism of aminophenols: Human keratinocytes as a suitable in vitro model to qualitatively predict the dermal transformation of 4-amino-2-hydroxytoluene in vivo. Toxicol App Pharmacol. 2009; 235(1):114-123. http://dx.doi.org/10.1016/j.taap.2008.11.014
20 Wolfram LJ Maibach HI Percutaneous penetration of hair dyes. Arch Dermatol Res. 1985; 277(3):235–241. http://dx.doi.org/10.1007/BF00404323 4015186
21 Eggenreich K Golouch S Töscher B Beck H Kuehnelt D Wintersteiger R Determination of 4-amino-m-cresol and 5-amino-o-cresol and metabolites in human keratinocytes (HaCaT) by high-performance liquid chromatography with DAD and MS detection. J Biochem Biophys Methods. 2004; 61(1-2):23–34. http://dx.doi.org/10.1016/j.jbbm.2004.04.021 15560919
22 Ogiso T Shiraki T Okajima K Tanino T Iwaki M Wada T Transfollicular drug delivery: penetration of drugs through human scalp skin and comparison of penetration between scalp and abdominal skins in vitro. J Drug Target. 2002; 10(5):369–378. http://dx.doi.org/10.1080/1061186021000001814 12442807
23 Lloyd GK Liggett MP Kynoch SR Davies RE Assessment of the acute toxicity and potential irritancy of hair dye constituents. Food Cosmet Toxicol. 1977; 15(6):607–610. http://dx.doi.org/10.1016/0015-6264(77)90077-3 604238
24 National Toxicology Program (NTP). Final report. Assessment of contact hypersensitivity to 5 amino-o-cresol in female BALB/c mice. Richmond, VA: Prepared by: Medical College of Virginia, VCU; 2006.
25 Takkouche B Regueira-Méndez C Montes-Martínez A Risk of cancer among hairdressers and related workers: a meta-analysis. Int J Epidemiol. 2009; 38(6):1512–1531. http://dx.doi.org/10.1093/ije/dyp283 19755396
26 International Agency for Research on Cancer (IARC). Occupational Exposures of Hairdressers and Barbers and Personal Use of Hair Colorants. Lyon, France: IARC; 1993. IARC Monographs on the Evaluation of Carcinogenic Risks to Humans. Some hair dyes, cosmetic colourants, industrial dyestuffs, and aromatic amines; p. 43–118.
27 Altekruse SF Henley SJ Thun MJ Deaths from hematopoietic and other cancers in relation to permanent hair dye use in a large prospective study (United States). Cancer Causes Control. 1999; 10(6):617–625. http://dx.doi.org/10.1023/A:1008926027805 10616830
28 Gago-Dominguez M Bell DA Watson MA Yuan J-M Castelao JE Hein DW Chan KK Coetzee GA Ross RK Yu MC Permanent hair dyes and bladder cancer: risk modification by cytochrome P4501A2 and N-acetyltransferases 1 and 2. Carcinogenesis. 2003; 24(3):483–489. http://dx.doi.org/10.1093/carcin/24.3.483 12663508
29 Gago‐Dominguez M, Castelao JE, Yuan JM, Yu MC, Ross RK. Use of permanent hair dyes and bladder‐cancer risk. Int J Cancer. 2001; 91(4):575-579. http://dx.doi.org/10.1002/1097-0215(200002)9999:9999<::AID-IJC1092>3.0.CO;2-S
30 Heineman EF Ward MH McComb RD Weisenburger DD Zahm SH Hair dyes and risk of glioma among Nebraska women. Cancer Causes Control. 2005; 16(7):857–864. http://dx.doi.org/10.1007/s10552-005-3204-z 16132796
31 Zahm SH Blair A Fraumeni JF Jr Hair coloring products: safe or still suspect? J Natl Cancer Inst. 1994; 86(12):941–944. http://dx.doi.org/10.1093/jnci/86.12.941-a 8196085
32 Zahm SH Weisenburger DD Babbitt PA Saal RC Vaught JB Blair A Use of hair coloring products and the risk of lymphoma, multiple myeloma, and chronic lymphocytic leukemia. Am J Public Health. 1992; 82(7):990–997. http://dx.doi.org/10.2105/AJPH.82.7.990 1609918
33 Zhang Y Holford TR Leaderer B Boyle P Zahm SH Flynn S Tallini G Owens PH Zheng T Hair-coloring product use and risk of non-Hodgkin’s lymphoma: a population-based case-control study in Connecticut. Am J Epidemiol. 2004; 159(2):148–154. http://dx.doi.org/10.1093/aje/kwh033 14718216
34 Zeiger E Anderson B Haworth S Lawlor T Mortelmans K Salmonella mutagenicity tests: IV. Results from the testing of 300 chemicals. Environ Mol Mutagen. 1988; 11 Suppl 12:1–157. http://dx.doi.org/10.1002/em.2850110602 3277844
35 Witt KL Livanos E Kissling GE Torous DK Caspary W Tice RR Recio L Comparison of flow cytometry- and microscopy-based methods for measuring micronucleated reticulocyte frequencies in rodents treated with nongenotoxic and genotoxic chemicals. Mutat Res. 2008; 649(1-2):101–113. http://dx.doi.org/10.1016/j.mrgentox.2007.08.004 17869571
36 Research Triangle Institute (RTI). Preliminary chemistry studies report. Research Triangle Park, NC: RTI; 2003. NIH Contract No. N01-ES-05455, RTI Project No. 07939.004.016.
37 Maronpot RR Boorman GA Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982; 10(2):71–78. http://dx.doi.org/10.1177/019262338201000210 28094716
38 Boorman GA Montgomery CA Jr Eustis SL Wolfe MJ McConnell EE Hardisty JF Quality assurance in pathology for rodent carcinogenicity studies. In: Milman HA Weisburger EKeditors. Handbook of carcinogen testing. Park Ridge (NJ): Noyes Publications; 1985. p. 345–357.
39 Gart JJ Chu KC Tarone RE Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979; 62(4):957–974. 285297
40 Dunnett CW A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955; 50(272):1096–1121.http://dx.doi.org/10.1080/01621459.1955.10501294
41 Williams DA The comparison of several dose levels with a zero dose control. Biometrics. 1972; 28(2):519–531. http://dx.doi.org/10.2307/2556164 5037867
42 Williams DA A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971; 27(1):103–117. http://dx.doi.org/10.2307/2528930 5547548
43 Shirley E. A non-parametric equivalent of Williams' test for contrasting increasing dose levels of a treatment. Biometrics. 1977:386-389. http://dx.doi.org/10.2307/2529789
44 Williams DA A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986; 42(1):183–186. http://dx.doi.org/10.2307/2531254 3719054
45 Dunn OJ Multiple comparisons using rank sums. Technometrics. 1964; 6(3):241–252.http://dx.doi.org/10.1080/00401706.1964.10490181
46 Jonckheere A A distribution-free k-sample test against ordered alternatives. Biometrika. 1954; 41:133–145.http://dx.doi.org/10.1093/biomet/41.1-2.133
47 Dixon W Massey F Introduction to statistical analysis. New York (NY): McGraw Hill Book Company Inc; 1957. 10.2307/2332898
48 Girard D, Sager D. The use of Markov chains to detect subtle variation in reproductive cycling. Biometrics. 1987:225-234. http://dx.doi.org/10.2307/2531963
49 Code of Federal Regulations (CFR). 21:Part 58.
50 MacGregor JT Wehr CM Henika PR Shelby MD The in vivo erythrocyte micronucleus test: measurement at steady state increases assay efficiency and permits integration with toxicity studies. Fundam Appl Toxicol. 1990; 14(3):513–522. http://dx.doi.org/10.1016/0272-0590(90)90255-I 2111256
51 Shelby MD Erexson GL Hook GJ Tice RR Evaluation of a three-exposure mouse bone marrow micronucleus protocol: results with 49 chemicals. Environ Mol Mutagen. 1993; 21(2):160–179. http://dx.doi.org/10.1002/em.2850210210 8444144
52 Hayashi M, Sofuni T, Ishidate M Jr. An application of acridine orange fluorescent staining to the micronucleus test. Mutat Res Lett. 1983; 120(4):241-247. http://dx.doi.org/10.1016/0165-7992(83)90096-9
53 Kissling GE Dertinger SD Hayashi M MacGregor JT Sensitivity of the erythrocyte micronucleus assay: dependence on number of cells scored and inter-animal variability. Mutat Res. 2007; 634(1-2):235–240. http://dx.doi.org/10.1016/j.mrgentox.2007.07.010 17851117
54 Christian M Final report on the safety assessment of 4-amino-2-hydroxytoluene. J Am Coll Toxicol. 1989; 8(4):569–587.http://dx.doi.org/10.3109/10915818909010523
55 Baan R Straif K Grosse Y Secretan B El Ghissassi F Bouvard V Benbrahim-Tallaa L Cogliano V WHO International Agency for Research on Cancer Monograph Working Group Carcinogenicity of some aromatic amines, organic dyes, and related exposures. Lancet Oncol. 2008; 9(4):322–323. http://dx.doi.org/10.1016/S1470-2045(08)70089-5 18405853
56 Argyris TS Klein-Szanto A Regeneration and the mechanism of epidermal tumor promotion. Crit Rev Toxicol. 1985; 14(3):211–258. http://dx.doi.org/10.3109/10408448509037459 3893895
57 Hennings H Boutwell RK Studies on the mechanism of skin tumor promotion. Cancer Res. 1970; 30(2):312–320. 5458969
58 Pullinger BD A measure of the stimulating effect of simple injury combined with carcinogenic chemicals on tumour formation in mice. J Pathol Bacteriol. 1945; 57(4):477–481. http://dx.doi.org/10.1002/path.1700570411 21012478
59 Cannon RE, Spalding JW, Trempus CS, Szczesniak CJ, Virgil KM, Humble MC, Tennant RW. Kinetics of wound‐induced v‐Ha‐ras transgene expression and papilloma development in transgenic Tg. AC mice. Mol Carcinog. 1997; 20(1):108-114. http://dx.doi.org/10.1002/(SICI)1098-2744(199709)20:1<108::AID-MC12>3.0.CO;2-5
60 Tennant RW, Stasiewicz S, Eastin WC, Mennear JH, Spalding JW. The Tg. AC (v-Ha-ras) transgenic mouse: Nature of the model. Toxicol Pathol. 2001; 29(1_suppl):51-59. http://dx.doi.org/10.1080/019262301753178474
61 Tennant RW Margolin BH Shelby MD Zeiger E Haseman JK Spalding J Caspary W Resnick M Stasiewicz S Anderson B Prediction of chemical carcinogenicity in rodents from in vitro genetic toxicity assays. Science. 1987; 236(4804):933–941. http://dx.doi.org/10.1126/science.3554512 3554512
62 Zeiger E Mutagens that are not carcinogens: faulty theory or faulty tests? Mutat Res. 2001; 492(1-2):29–38. http://dx.doi.org/10.1016/S1383-5718(01)00153-X 11377241
63 Hayamizu K, Yanagisawa M, Yamamoto O, Wasada N, Someno K, Tanabe K, Tamura T, Hiraishi J. National Institute of Advanced Industrial Science and Technology. Tsukuba, Ibaraki, Japan; 2006. http://www.aist.go.jp/RIODB/SDBS/menu-e.html
64 Pouchert CJeditor. The Aldrich library of infrared spectra. Milwaukee (WI): Aldrich Chemical Company Inc.; 1981.