# Discussion

The toxic and carcinogenic properties of hair dyes and their components have previously been reviewed by the international community under the sponsorship of the International Agency for Research on Cancer (IARC).^11,26^ Hair dyes may be classified into the following categories: oxidative (permanent) dyes, direct (temporary or semipermanent) dyes, and natural dyes.^11^ Occupational exposures to hair dyes are probably carcinogenic to humans (classified as IARC Group 2A, “probably carcinogenic to humans”). Personal use of hair colorants is not classifiable as to its carcinogenicity to humans (IARC Group 3, “not classifiable as to its carcinogenicity to humans”).

Because there had been no previous carcinogenesis studies on the oxidative hair dye, 5-amino-o-cresol, NTP conducted dermal toxicity studies to determine the level of toxicity in rodents and the need for 2-year dermal carcinogenicity studies.

The current NTP studies in F344/NTac rats and B6C3F1/N mice showed that skin toxicity did not occur after 3 months of dermal administration of 5-amino-o-cresol at doses up to 32 mg/kg body weight per day in rats and 128 mg/kg per day in mice. Mean body weights of dosed rats and mice were within 6% to 8% of the vehicle controls. No treatment-related mortality, gross or microscopic pathology findings, or effects on organ weights, clinical pathology endpoints, or reproductive endpoints were found in either species. While feed studies of 5-amino-o-cresol in rodents showed that when the chemical was administered at up to 3% (30,000 ppm) there was thyroid gland or liver toxicity in rats,^54^ there was no evidence for these target organ toxicities in the current studies. NTP studies have shown that dermal absorption of 5-amino-o-cresol is about 10% when applied to a covered site; however, when the dose site is not covered, as was the case in the current studies, the absorption increases (up to 60%) suggesting systemic exposure via both dermal and oral routes (due to grooming). Because the highest dose in this 5-amino-o-cresol rat study (32 mg/kg per body weight) was considerably lower than the dose (30,000 ppm) that caused liver and thyroid gland toxicity in the Christian^54^ feed study, no liver or thyroid gland toxicity was expected in the current rat study.

Other hair dye chemicals have been found to be carcinogenic in rodent studies, but for many of these studies the chemical was administered by the oral route of exposure to obtain a maximum systemic tolerated dose.^11,55^ In these studies of 5-amino-o-cresol, the dermal route of administration was selected to mimic human exposure. There was no evidence for 5-amino-o-cresol skin irritation in the dermal immunotoxicity studies. Chronic dermal irritation can lead to tumor promotion,^56-58^ and in transgenic mouse cancer models, skin irritation may lead to a dermal carcinogenic response.^59,60^ However, in these studies there was no indication of 5-amino-o-cresol skin irritation or skin toxicity. Although 5-amino-o-cresol is mutagenic in bacteria, not all bacterial mutagens are carcinogenic in rodent bioassays.^61,62^ While 5-amino-o-cresol was mutagenic in some of the Salmonella strains tested, it is not anticipated to be a rodent carcinogen by the dermal route of administration based on the lack of target organ lesions in the 3-month dermal 5-amino-o-cresol studies reported here and the limited 5-amino-o-cresol absorption by skin.