# Results

## Three-month Study in Rats

All rats survived to the end of the study (Table 2). Final mean body weights and body weight gains of male and female rats were similar to those of the vehicle controls (Table 2; Figure 3).

Table 2 Survival and Body Weights of Rats in the Three-month Dermal Study of 5-Amino-o-cresol^a^

Dose (mg/kg) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 10/10 | 77 ± 1 | 324 ± 6 | 247 ± 5
2 | 10/10 | 78 ± 1 | 324 ± 5 | 247 ± 5 | 100
4 | 10/10 | 76 ± 1 | 329 ± 7 | 252 ± 7 | 101
8 | 10/10 | 77 ± 1 | 339 ± 5 | 262 ± 5 | 104
16 | 10/10 | 77 ± 1 | 333 ± 7 | 256 ± 7 | 103
32 | 10/10 | 77 ± 1 | 333 ± 4 | 256 ± 4 | 103
Female
0 | 10/10 | 74 ± 1 | 186 ± 3 | 112 ± 2
2 | 10/10 | 74 ± 1 | 188 ± 4 | 114 ± 3 | 101
4 | 10/10 | 75 ± 2 | 192 ± 3 | 117 ± 2 | 103
8 | 10/10 | 74 ± 1 | 185 ± 3 | 112 ± 2 | 100
16 | 10/10 | 74 ± 2 | 187 ± 4 | 113 ± 3 | 101
32 | 10/10 | 73 ± 1 | 184 ± 3 | 111 ± 3 | 99

^a^ Weights and weight changes are given as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test.

^b^ Number of animals surviving at 14 weeks/number initially in group.

Figure 3

Growth Curves for Rats Administered 5-Amino-o-cresol Dermally for Three Months

There were no biologically significant differences between dosed and vehicle control groups in hematology or clinical chemistry parameters of clinical pathology study rats on days 4 or 23 or core study rats at week 14 (Table B-1).

Absolute and relative liver weights and absolute heart weight were significantly increased in 8 mg/kg males relative to the vehicle controls (Table C-1). Because there were no microscopic lesions corresponding to these organ weight increases and the increases were not observed in the other dosed groups, these increases were not considered treatment related.

Administration of 8, 16, or 32 mg/kg did not result in significant changes/differences in reproductive organ histopathology, sperm parameters of male rats, or the estrous cyclicity of female rats when compared to the vehicle controls (Table D-1 and Table D-2). Therefore, 5-amino-o-cresol did not exhibit any potential to be a reproductive toxicant in male or female rats under the conditions of this study.

There were no gross or histologic lesions that were considered related to treatment (Table A-1 and Table A-2). Incidences of chronic active inflammation of the lung in 8 mg/kg males and histocytic inflammation of the mesenteric lymph node in 32 mg/kg females were significantly greater than those in the vehicle controls. These lesions were considered background changes, and therefore, not considered biologically relevant or treatment related. No gross or histologic lesions were recorded in the skin of rats.

## Three-month Study in Mice

All male mice survived to the end of the study (Table 3); one 32 mg/kg female mouse died spontaneously on day 73. The final mean body weights and body weight gains of all dosed groups were similar to those of the vehicle control groups (Table 3; Figure 4). There were no treatment-related clinical findings in males or females. There were no statistically significant differences between dosed and vehicle control groups in hematology parameters (Table B-2) or in the absolute or relative organ weights (Table C-2).

Table 3 Survival and Body Weights of Mice in the Three-month Dermal Study of 5-Amino-o-cresol^a^

Dose (mg/kg) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 10/10 | 22.6 ± 0.2 | 41.8 ± 0.8 | 19.2 ± 0.8
8 | 10/10 | 22.8 ± 0.3 | 41.1 ± 0.9 | 18.4 ± 0.9 | 98
16 | 10/10 | 22.9 ± 0.3 | 42.3 ± 0.7 | 19.4 ± 0.7 | 101
32 | 10/10 | 23.0 ± 0.3 | 42.7 ± 1.1 | 19.7 ± 1.0 | 102
64 | 10/10 | 23.0 ± 0.4 | 42.1 ± 1.0 | 19.1 ± 1.0 | 101
128 | 10/10 | 23.0 ± 0.2 | 42.5 ± 1.1 | 19.5 ± 1.0 | 102
Female
0 | 10/10 | 18.7 ± 0.2 | 37.6 ± 1.0 | 18.9 ± 1.1
8 | 10/10 | 18.6 ± 0.2 | 37.7 ± 1.6 | 19.1 ± 1.5 | 100
16 | 10/10 | 19.4 ± 0.3 | 38.8 ± 1.1 | 19.5 ± 1.0 | 103
32 | 9/10^c^ | 19.1 ± 0.2 | 39.0 ± 1.5 | 19.9 ± 1.5 | 104
64 | 10/10 | 18.7 ± 0.3 | 36.4 ± 1.7 | 17.7 ± 1.4 | 97
128 | 10/10 | 18.7 ± 0.2 | 36.3 ± 1.1 | 17.6 ± 1.0 | 96

^a^ Weights and weight changes are given as mean ± standard error. Subsequent calculations are based on animals surviving to the end of the study. Differences from the vehicle control group are not significant by Dunnett’s test.

^b^ Number of animals surviving at 14 weeks/number initially in group.

^c^ Week of death: 11.

Figure 4

Growth Curves for Mice Administered 5-Amino-o-cresol Dermally for Three Months

Administration of 32, 64, or 128 mg/kg did not result in significant changes/differences in reproductive organ histopathology, sperm parameters of male mice, or the estrous cyclicity of female mice when compared to the vehicle controls (Table D-3 and Table D-4). Therefore, 5-amino-o-cresol did not exhibit any potential to be a reproductive toxicant in male or female mice under the conditions of this study.

There were no gross or histologic lesions that were considered treatment related (Table A-3 and Table A-4). The female mouse that died early had a benign teratoma of the left ovary. Teratomas are spontaneous congenital neoplasms unrelated to chemical administration. No gross or histologic lesions were recorded in the skin of mice.

## Genetic Toxicology

5-Amino-o-cresol (33 to 6,666 µg/plate, dissolved in dimethylsulfoxide) was tested for mutagenicity in four strains of Salmonella typhimurium (TA97, TA98, TA100, and TA1535), with and without 10% induced male rat or hamster liver S9 enzymes; it was positive in strains TA97, TA98, and TA100 in the presence of either species of S9^34^ (Table E-1). No mutagenicity was observed, however, in strain TA1535, with or without S9 activation enzymes. Among the three strains that gave positive responses, the strongest mutagenic response (based on fold-increase and lowest effective dose) was seen in strain TA98, a strain that reverts via frame shifting.

In vivo, no increases in micronucleated erythrocytes were observed in peripheral blood samples obtained from male or female B6C3F1/N mice in the 3-month toxicity study (Table E-2). In short-term tests for induction of micronuclei^35^ (Table E-3 and Table E-4), an initial test in male B6C3F1/N mice administered 5-amino-o-cresol (100 to 400 mg/kg per day) via gavage once daily for 3 days, was judged to be equivocal, based on a significant increase in micronucleated reticulocytes in bone marrow in the 100 mg/kg group (Table E-4; Trial 1). However, analysis of micronucleated reticulocytes in peripheral blood samples obtained from these same animals and measured using flow cytometry, showed no increases in micronuclei (Table E-3). In a repeat test, male B6C3F1/N mice were administered 50 to 400 mg/kg 5-amino-o-cresol by gavage once daily for 3 days and no increases in the frequencies of micronucleated reticulocytes were observed over the dose range tested (Table E-4; Trial 2). No significant changes in the percentage of reticulocytes were seen in any of the micronucleus tests conducted with 5-amino-o-cresol, suggesting that 5-amino-o-cresol did not induce bone marrow toxicity.