# Materials and Methods

## Procurement and Characterization

### 5-Amino-o-cresol

5-Amino-o-cresol was obtained from Fluka Chemical Company (Buchs, Switzerland) in one lot (385913/1) that was used in the 3-month dermal studies. Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at Research Triangle Institute (Research Triangle Park, NC) and the study laboratory at Battelle Columbus Operations (Columbus, OH) (Appendix F). Karl Fischer titration was performed by Galbraith Laboratories (Knoxville, TN). Reports on analyses performed in support of the 5-amino-o-cresol studies are on file at the National Institute of Environmental Health Sciences.

The chemical, a beige powder, was identified as 5-amino-o-cresol using infrared spectroscopy, nuclear magnetic resonance spectroscopy, gas chromatography (GC) with mass spectrometry, and melting point determination. Karl Fischer titration was used to determine the water content of the test chemical. The purity of lot 385913/1 was determined using GC with flame ionization detection (FID) and high-performance liquid chromatography (HPLC) with ultraviolet light (UV) detection.

Karl Fischer titration indicated a range of 0.14% to 0.48% water. GC/FID analysis by one system indicated one major peak with three impurities greater than 0.1% of the total peak area, with a combined total of 0.80% of the total peak area. GC/FID analysis by a second system indicated one major peak and one impurity with an area of 0.37% relative to the total peak area. HPLC/UV indicated one major peak and no impurities. The overall purity of lot 385913/1 was estimated to be greater than 99%.

Stability studies of the bulk chemical were performed using GC/FID. These studies indicated that 5-amino-o-cresol was stable as a bulk chemical for at least 2 weeks when stored protected from light at temperatures up to 25°C. To ensure stability, the test chemical was stored in sealed amber glass vials at room temperature (~25°C). Periodic reanalyses of the test chemical were performed using HPLC/UV and no degradation was observed.

### Ethanol

USP-grade 95% ethanol was obtained from Spectrum Chemicals and Laboratory Products (Gardena, CA) in one lot (UO0008) that was used as the vehicle in the 3-month dermal studies. Identity, purity, and trace benzene analyses were conducted by the study laboratory.

The chemical, a clear liquid, was confirmed as ethanol using infrared spectroscopy. Purity of the bulk chemical was determined using GC/FID; no impurities greater than 0.1% of the total peak area were detected by one system, and no benzene was detected by a second system. The overall purity of lot UO0008 was determined to be greater than 99%.

The bulk chemical was stored normally at ambient conditions. Reanalyses using GC/FID detected no degradation of the vehicle.

## Preparation and Analysis of Dose Formulations

The dose formulations were prepared four times by mixing 5-amino-o-cresol with 95% ethanol to give the required concentrations. Stability studies of the 4 mg/mL dose formulation were performed by the analytical chemistry laboratory using HPLC/UV. Stability was confirmed for at least 42 days for dose formulations stored in glass containers sealed with Teflon^®^-lined lids, protected from light, at temperatures up to 25°C, and for 3 hours under simulated animal room conditions.

Analyses of the dose formulations of 5-amino-o-cresol were conducted three times by the study laboratory using HPLC/UV; animal room samples of these dose formulations were also analyzed (Table F-4). All 15 dose formulations analyzed for rats and mice were within 10% of the target concentrations; all 15 animal room samples for rats and all 15 for mice were within 10% of the target concentrations.

## Dose Selection Rationale

5-Amino-o-cresol was administered by the dermal route to mimic human exposure to the chemical from hair dye use. The solubility of 5-amino-o-cresol was limited to approximately 60 mg/mL in ethanol.^36^ For the rat study, stock solutions of 0, 4, 8, 16, 32, or 64 mg 5-amino-o-cresol/mL were prepared in 95% ethanol and applied at 0.5 mL/kg body weight to deliver 0, 2, 4, 8, 16, or 32 mg 5-amino-o-cresol/kg body weight. For the mouse study, stock solutions of 0, 4, 8, 16, 32, or 64 mg/mL were prepared in 95% ethanol and applied at 2.0 mL/kg to deliver 0, 8, 16, 32, 64, or 128 mg/kg. The five doses included the maximum dose that could be administered by the dermal route.

## Three-month Studies

Male and female F344/NTac rats and B6C3F1/N mice were obtained from Taconic Farms, Inc. (Germantown, NY). On receipt, the rats were 3 to 4 weeks old and the mice were 4 to 5 weeks old. Animals were quarantined for 11 or 12 days (rats) or 13 or 14 days (mice); rats were 5 to 6 weeks old and mice were 6 to 7 weeks old on the first day of the studies. Before the studies began, five male and five female rats and mice were randomly selected for parasite evaluation and gross observation for evidence of disease. Serologic analyses were performed on five male and five female sentinel rats and mice at 4 weeks and five male and four or five female rats and mice at the end of the studies using the protocols of the NTP Sentinel Animal Program (Appendix H). All test results were negative.

Groups of 10 male and 10 female core study rats were dermally administered 0, 2, 4, 8, 16, or 32 mg/kg 5 days per week for 14 weeks; additional groups of 10 male and 10 female clinical pathology study rats were administered the same doses for 23 days. Groups of 10 male and 10 female mice were administered 0, 8, 16, 32, 64, or 128 mg/kg for 14 weeks. Doses were administered in 95% ethanol at volumes of 0.5 mL/kg (rats) or 2 mL/kg (mice); vehicle control animals received the 95% ethanol vehicle only. Doses were applied once daily to the dorsal skin application site, which was clipped weekly. Feed and water were available ad libitum. Animal care and use are in accordance with the public Health Service Policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by the Association for the Assessment and Accreditation of Laboratory Animal Care International. Studies were approved by the Battelle Columbus Operations Animal Care and Use Committee and conducted in accordance with all relevant NIH and NTP animal care and use policies and applicable federal, state, and local regulations and guidelines. Rats and mice were housed individually. All animals were weighed and clinical findings were recorded on day 1, weekly, and at the end of the studies. Details of the study design and animal maintenance are summarized in Table 1. Information on feed composition and contaminants is provided in Appendix G.

Table 1 Experimental Design and Materials and Methods in the Studies of 5-Amino-o-cresol

Three-month Dermal Studies
Study Laboratory
Battelle Columbus Operations (Columbus, OH)
Strain and Species
F344/NTac rats B6C3F1/N mice
Animal Source
Taconic Farms, Inc. (Germantown, NY)
Time Held Before Studies
Rats: 11 (males) or 12 (females) days Mice: 13 (females) or 14 (males) days
Average Age When Studies Began
Rats: 5 to 6 weeks Mice: 6 to 7 weeks
Date of First Dose
Rats: May 8 (males) or 9 (females), 2006 Mice: May 10 (females) or 11 (males), 2006
Duration of Dosing
5 days per week for 23 days (clinical pathology study rats) or 14 weeks (core study rats and mice)
Date of Last Dose
Rats (clinical pathology study): May 30 (males) or 31 (females), 2006 Rats (core study): August 7 (males) or 8 (females), 2006 Mice: August 9 (females) or 10 (males), 2006
Necropsy Dates
Rats (core study): August 8 (males) or 9 (females), 2006 Mice: August 10 (females) or 11 (males), 2006
Average Age at Necropsy
Rats: 18 to 19 weeks Mice: 19 to 20 weeks
Size of Study Groups
10 males and 10 females
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights.
Animals per Cage
1
Method of Animal Identification
Tail tattoo
Diet
Irradiated NTP-2000 open formula wafer feed (Zeigler Brothers, Inc., Gardners, PA), available ad libitum; changed at least weekly
Water
Tap water (City of Columbus municipal supply) via automatic watering system (Edstrom Industries, Waterford, WI), available ad libitum
Cages
Polycarbonate [Allentown Caging Equipment Company, Allentown, NJ (rats) or Lab Products, Inc., Seaford, DE (mice)], changed weekly
Bedding
Irradiated Sani Chips^®^ (P.J. Murphy Forest Products Corp., Montville, NJ), changed weekly
Rack Filters
Spun-bonded polyester (Snow Filtration, Cincinnati, OH) changed every 2 weeks
Racks
Stainless steel (Lab Products, Inc., Seaford, DE), changed every 2 weeks
Animal Room Environment
Temperature: 72° ± 3°F Relative humidity: 50% ± 15% Room fluorescent light: 12 hours/day Room air changes: at least 10/hour
Doses
Rats: 0, 2, 4, 8, 16, or 32 mg/kg in 95% ethanol (dosing volume, 0.5 mL/kg)
Mice: 0, 8, 16, 32, 64, or 128 mg/kg in 95% ethanol (dosing volume, 2 mL/kg)
Type and Frequency of Observation
Observed twice daily; animals were weighed and clinical findings were recorded on day 1, weekly thereafter, and at the end of the studies.
Method of Kill
Carbon dioxide asphyxiation
Necropsy
Necropsies were performed on all core study rats and mice. Organs weighed were heart, right kidney, liver, lung, right testis, and thymus.
Clinical Pathology
Blood was collected from the retroorbital sinus of clinical pathology study rats on days 4 and 23 and from core study animals at the end of the studies for hematology and clinical chemistry (rats only). Hematology: hematocrit; hemoglobin; erythrocyte, reticulocyte, and platelet counts; mean cell volume; mean cell hemoglobin; mean cell hemoglobin concentration; and leukocyte count and differentials Clinical Chemistry: urea nitrogen, creatinine, glucose, total protein, albumin, alanine aminotransferase, alkaline phosphatase, creatine kinase, sorbitol dehydrogenase, bile acids, and total thyroxine
Histopathology
Complete histopathology was performed on core study rats in the 0 and 32 mg/kg groups and mice in the 0 and 128 mg/kg groups. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone (femur) with marrow, brain, clitoral gland, esophagus, eye, gallbladder (mice), Harderian gland, heart and aorta, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, liver, lung (with mainstem bronchus), lymph nodes (mandibular and mesenteric), mammary gland with adjacent (inguinal) skin, nose, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, seminal vesicle, skin (site of application), spleen, stomach (forestomach and glandular), testis (with epididymis), thymus, thyroid gland, trachea, urinary bladder, and uterus.
Sperm Motility and Vaginal Cytology
At the end of the studies, sperm samples were collected from male rats in the 0, 8, 16, and 32 mg/kg groups and male mice in the 0, 32, 64, and 128 mg/kg groups for sperm motility evaluations. The following parameters were evaluated: spermatid heads per gram testis and per testis, and epididymal spermatozoal motility and concentration. The left cauda, left epididymis, and left testis were weighed. Vaginal samples were collected for up to 16 consecutive days prior to the end of the studies from female rats in the 0, 8, 16, and 32 mg/kg groups and female mice in the 0, 32, 64, and 128 mg/kg groups for vaginal cytology evaluations.

Animals were anesthetized with a carbon dioxide/oxygen mixture. Blood was collected from the retroorbital plexus of clinical pathology study rats on days 4 and 23 and core study rats at the end of the studies for hematology and clinical chemistry endpoints. Blood was collected from the retroorbital sinus of mice at the end of the studies for hematology endpoints. Blood samples for hematology were collected in tubes containing EDTA. Blood samples for clinical chemistry were placed in serum separator tubes. Hematology parameters were measured using an ADVIA^®^ 120 Hematology Analyzer (Bayer Diagnostics Division, Tarrytown, NY). Clinical chemistry parameters were determined using the Hitachi 911 chemical analyzer (Roche Diagnostics, Indianapolis, IN). The parameters measured are listed in Table 1.

At the end of the 3-month studies, samples were collected for sperm motility or vaginal cytology evaluations on male and female rats in the 0, 8, 16, and 32 mg/kg groups and male and female mice in the 0, 32, 64, and 128 mg/kg groups. The parameters evaluated are listed in Table 1. For 16 consecutive days prior to scheduled terminal sacrifice, the vaginal vaults of the females were moistened with saline, if necessary, and samples of vaginal fluid and cells were stained. Relative numbers of leukocytes, nucleated epithelial cells, and large squamous epithelial cells were determined and used to ascertain estrous cycle stage (i.e., diestrus, proestrus, estrus, and metestrus). Male animals were evaluated for sperm count and motility. The left testis and left epididymis were isolated and weighed. The tail of the epididymis (cauda epididymis) was then removed from the epididymal body (corpus epididymis) and weighed. Test yolk (rats) or modified Tyrode’s buffer (mice) was applied to slides and a small incision was made at the distal border of the cauda epididymis. The sperm effluxing from the incision were dispersed in the buffer on the slides, and the numbers of motile and nonmotile spermatozoa were counted for five fields per slide by two observers. Following completion of sperm motility estimates, each left cauda epididymis was placed in buffered saline solution. Caudae were finely minced, and the tissue was incubated in the saline solution and then heat fixed at 65°C. Sperm density was then determined microscopically with the aid of a hemacytometer. To quantify spermatogenesis, the testicular spermatid head count was determined by removing the tunica albuginea and homogenizing the left testis in phosphate-buffered saline containing 10% dimethyl sulfoxide. Homogenization-resistant spermatid nuclei were counted with a hemacytometer.

Necropsies were performed on all core study rats and mice. The heart, right kidney, liver, lung, right testis, and thymus were weighed. Tissues for microscopic examination were fixed and preserved in 10% neutral buffered formalin (eyes were first fixed in Davidson’s solution), processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin. Complete histopathologic examinations (organs listed in Table 1) were performed by the study laboratory pathologist on rats in the 0 and 32 mg/kg groups and mice in the 0 and 128 mg/kg groups. In addition, the kidneys and lungs of mice were examined from all dose groups, and the thyroid gland, liver, and lung were examined from all dose groups of rats.

After a review of the laboratory reports and selected histopathology slides by a quality assessment (QA) pathologist, the findings and reviewed slides were submitted to a NTP Pathology Working Group (PWG) coordinator for a second independent review. Any inconsistencies in the diagnoses made by the study laboratory and QA pathologists were resolved by the NTP pathology peer review process. Final diagnoses for reviewed lesions represent a consensus of the PWG or a consensus between the study laboratory pathologist, NTP pathologist, QA pathologist(s) and the PWG coordinator. Details of these review procedures have been described, in part, by Maronpot and Boorman^37^ and Boorman et al.^38^

## Statistical Methods

### Calculation and Analysis of Lesion Incidences

The incidences of lesions are presented in Appendix A as the numbers of animals bearing such lesions at a specific anatomic site and the numbers of animals with that site examined microscopically. The Fisher exact test,^39^ a procedure based on the overall proportion of affected animals, was used to determine significance.

### Analysis of Continuous Variables

Two approaches were employed to assess the significance of pairwise comparisons between dosed and vehicle control groups in the analysis of continuous variables. Organ and body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^40^ and Williams.^41,42^ Hematology, clinical chemistry, spermatid, and epididymal spermatozoal data, which have typically skewed distributions, were analyzed using the nonparametric multiple comparison methods of Shirley^43^ (as modified by Williams^44^) Dunn.^45^ Jonckheere’s test^46^ was used to assess the significance of the dose-related trends and to determine whether a trend-sensitive test (Williams’ or Shirley’s test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic dose-related trend (Dunnett’s or Dunn’s test). Prior to statistical analysis, extreme values identified by the outlier test of Dixon and Massey^47^ were examined by NTP personnel, and implausible values were eliminated from the analysis. Proportions of regular cycling females in each dosed group were compared to the vehicle control group using the Fisher exact test.^39^ Tests for extended periods of estrus, diestrus, metestrus, and proestrus, as well as skipped estrus and skipped diestrus, were constructed based on a Markov chain model proposed by Girard and Sager.^48^ For each dose group, a transition probability matrix was estimated for transitions among the proestrus, estrus, metestrus, and diestrus stages, with provision for extended stays within each stage as well as for skipping estrus or diestrus within a cycle. Equality of transition matrices among dose groups and between the vehicle control group and each dosed group was tested using chi-square statistics.

## Quality Assurance Methods

The 3-month studies were conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations.^49^ The Quality Assurance Unit of Battelle Columbus Operations performed audits and inspections of protocols, procedures, data, and reports throughout the course of the studies.

## Genetic Toxicology

### Salmonella typhimurium Mutagenicity Test Protocol

Testing procedures used at BioReliance Corporation followed protocols reported by Zeiger et al.^34^ 5-amino-o-cresol was sent to the laboratory as a coded sample. It was incubated with the Salmonella typhimurium tester strains TA97, TA98, TA100, and TA1535 either in buffer or S9 mix (metabolic activation enzymes and cofactors from Aroclor 1254-induced male Sprague Dawley rat or Syrian hamster liver) for 20 minutes at 37°C. Top agar supplemented with L-histidine and d-biotin was added, and the contents of the tubes were mixed and poured onto the surfaces of minimal glucose agar plates. Histidine-independent mutant colonies arising on these plates were counted following incubation for 2 days at 37°C.

Each trial consisted of triplicate plates of concurrent positive and negative controls and of five doses of 5-amino-o-cresol. The high dose was limited by toxicity. All trials that produced a positive response were repeated.

In this assay, a positive response is defined as a reproducible, dose-related increase in histidine-independent (revertant) colonies in any one strain/activation combination. An equivocal response is defined as an increase in revertants that is not dose related, is not reproducible, or is not of sufficient magnitude to support a determination of mutagenicity. A negative response is obtained when no increase in revertant colonies is observed following chemical treatment. There is no minimum percentage or fold increase required for a chemical to be judged positive or weakly positive although positive calls are typically reserved for increases in mutant colonies that are at least twofold over background.

### Mouse Peripheral Blood and Bone Marrow Micronucleus Test Protocols

#### Slide-Based Assay

A detailed discussion of this assay is presented by MacGregor et al.^50^ At the termination of the 3-month dermal toxicity study, peripheral blood samples were obtained from male and female mice. Smears were immediately prepared and fixed in absolute methanol. The methanol-fixed slides were stained with acridine orange and coded. Slides were scanned to determine the frequency of micronucleated cells in 2,000 normochromatic erythrocytes (NCEs) in each of five animals per dose group. In addition, the percentage of polychromatic erythrocytes (PCEs; reticulocytes) in a population of 1,000 erythrocytes was determined as a measure of bone marrow toxicity.

Four or five male B6C3F1/N mice per dose group were administered 5-amino-o-cresol in corn oil by gavage at 24-hour intervals for 3 days; vehicle control animals received corn oil alone.^35,51^ The positive control was cyclophosphamide. Twenty-four hours after the final treatment, the animals were euthanized and smears of the bone marrow cells obtained from the femurs were prepared. Two trials were conducted.

For bone marrow slide evaluation, air-dried slides were fixed in absolute methanol and stained with acridine orange.^52^ Two thousand PCEs were scored per animal for frequency of micronucleated cells. In addition, the percentage of PCEs among 500 erythrocytes in bone marrow was scored per animal as a measure of bone marrow toxicity.

The results were tabulated as the mean of the pooled results from all animals within a treatment group, plus or minus the standard error of the mean. The frequency of micronucleated cells among NCEs or PCEs was analyzed by a statistical software package that tested for increasing trend over dose groups using a one-tailed Cochran-Armitage trend test, followed by pairwise comparisons between each dosed group and the vehicle control group. In the presence of excess binomial variation, as detected by a binomial dispersion test, the binomial variance of the Cochran-Armitage test was adjusted upward in proportion to the excess variation. In the slide-based micronucleus test, an individual trial is considered positive if the trend test P value is less than or equal to 0.025 or if the P value for any single dosed group is less than or equal to 0.025 divided by the number of dosed groups. A final call of positive for micronucleus induction is preferably based on reproducibly positive trials (as noted above). Ultimately, the scientific staff determines the final call after considering the results of statistical analyses, reproducibility of any effects observed, and the magnitudes of those effects.

#### Flow Cytometric Assay

Blood samples (6 to 120 µL) were obtained from mice used in bone marrow trial 1. Blood was drawn into tubes containing heparin, fixed in ultracold methanol, and frozen at −80°C until analysis. Thawed blood samples were analyzed for frequency of micronucleated PCEs and NCEs using a flow cytometer^35^; both the mature erythrocyte population and the immature reticulocyte population can be accurately distinguished using flow cytometry by employing special cell surface markers to differentiate the two cell types. Approximately 20,000 PCEs and 1 million NCEs were analyzed per animal; the percentage of PCEs among circulating erythrocytes was also determined as a measure of bone marrow toxicity.

Based on prior experience with the large number of cells scored using flow cytometric scoring techniques,^53^ it is reasonable to assume that the proportion of micronucleated PCEs is approximately normally distributed. The statistical tests selected for trend and for pairwise comparisons with the vehicle control group depend on whether the variances among the groups are equal. Levene’s test at α = 0.05 is used to test for equal variances. In the case of equal variances, linear regression is used to test for a linear trend with dose and Williams’ test^41,42^ is used to test for pairwise differences between each treated group and the vehicle control group. In the case of unequal variances, Jonckheere’s test^46^ is used to test for linear trend and Dunn’s test^45^ is used for pairwise comparisons of each treated group with the vehicle control group. Trend tests and pairwise comparisons with the vehicle controls are considered statistically significant at P = 0.025. Ultimately, the scientific staff determines the final call after considering the results of statistical analyses, reproducibility of any effects observed, and the magnitudes of those effects.

### Evaluation Protocol

These are the basic guidelines for arriving at an overall assay result for assays performed by the National Toxicology Program. Statistical as well as biological factors are considered. For an individual assay, the statistical procedures for data analysis have been described in the preceding protocols. There have been instances, however, in which multiple aliquots of a chemical were tested in the same assay, and different results were obtained among these aliquots and/or among laboratories. Results from more than one aliquot or from more than one laboratory are not simply combined into an overall result. Rather, all the data are critically evaluated, particularly with regard to pertinent protocol variations, in determining the weight of evidence for an overall conclusion of chemical activity in an assay. In addition to multiple aliquots, the in vitro assays have another variable that must be considered in arriving at an overall test result. In vitro assays are conducted with and without exogenous metabolic activation. Results obtained in the absence of activation are not combined with results obtained in the presence of activation; each testing condition is evaluated separately. The results presented in the Abstract of this Toxicity Study Report represent a scientific judgment of the overall evidence for activity of the chemical in an assay.