# Introduction

Figure 1

5-Amino-o-cresol (CASRN 2835-95-2; Chemical Formula: C_7_H_9_NO; Molecular Weight: 123.17)

Synonyms: 4-Amino-2-hydroxy-1-methylbenzene; 4-amino-2-hydroxytoluene; 3-amino-6-methylphenol; 5-amino-2-methylphenol; 2-hydroxy-4-aminotoluene; 3-hydroxy-4-methylaniline; 2-hydroxy-p-toluidine; 2-methyl-5-aminophenol; 6-methyl-3-aminophenol.

## Chemical and Physical Properties

5-Amino-o-cresol is a beige powder with solubility in water of 2,427 mg/L, and it reacts with oxidizing agents.^1^ It has a melting point of 160°C and a log octanol:water partition coefficient of 0.79.^2,3^

## Production, Use, and Human Exposure

5-Amino-o-cresol is the most widely used member of a class of 25 chemicals, the aminocresols and related compounds, defined as amino- and methyl-substituted phenols, their salts, and ethers. 5-Amino-o-cresol (4-amino-2-hydroxytoluene) is used as an oxidative dye coupler (secondary intermediate) or oxidative (permanent) in hair dye formulations.^4,5^ Use of the aminophenols as hair dyes (including 5-amino-o-cresol) began in the 19th century.^6^ In 2006, 5-amino-o-cresol was used in 628 hair dye and color products, in 12 tint products, and one lightener product; the average concentration for this hair dye product ranged from 0.2% to 2%.^5^

The number of barbers, hairdressers, and cosmetologists employed in the United States in 2010 was estimated to be 712,200 by the Bureau of Labor Statistics (BLS).^7^ This group may be exposed to 5-amino-o-cresol as a component in hair dyes. It is estimated that more than one third of women over age 18 and about 10 percent of men over age 40 use some type of hair dye.^8,9^ The National Occupational Exposure Survey, between 1981 and 1983, estimated that 44,842 employees were potentially exposed to 5-amino-o-cresol in the workplace.^10^

The estimated worldwide use of 5-amino-o-cresol is 150 to 250 tons per year (data provided by the international hair-dye industry and covers approximately 90% of the world market^11^).

## Regulatory Status

Hair dyes and hair dye ingredients are regulated as cosmetic products by the Food and Drug Administration (FDA).^12^ Cosmetics produced or distributed for retail sale to consumers for their personal care are required to list ingredients. Hair preparations used by professionals at their establishments and places of work are exempt from this requirement provided that these products are not sold to consumers for home use.

The FDA restricts the use of certain color additives under the Federal Food, Drug, and Cosmetic (FD&C) Act. These restrictions are contained in the Code of Federal Regulations.^13-15^ Under the FD&C Act, the FDA does not have authority to require premarket approval for cosmetics, but it can take action when safety issues surface.^12,16^

Various United States patents have been issued for 5-amino-o-cresol.^4^ 5-Amino-o-cresol is used in the production of neutral red color shades.^17^

## Absorption, Distribution, Metabolism, and Excretion

### Experimental Animals

NTP conducted absorption, distribution, metabolism, and excretion studies of 5-amino-o-cresol in female F344/N rats and female B6C3F1 mice following single gavage administration, intravenous administration, or dermal application.^18^ Absorption of 5-amino-o-cresol was complete following gavage administration in rats (4 to 357 mg/kg) and mice (36 mg/kg). Excretion was mainly in the urine, and more than 80% of the administered dose was excreted in the urine within 24 hours. Absorption of 5-amino-o-cresol in rats 24 or 72 hours following dermal application (protected from oral grooming) was less than 10% of the applied dose (2.5 or 26 mg/kg; the application site was rinsed 6 hours after application). When the dermal site was unprotected from grooming, 36% to 66% of the applied dose (2.5 to 32 mg/kg) was absorbed within 24 or 72 hours indicating that the oral exposure through grooming contributes significantly to the total absorbed dose. As observed following oral or intravenous administration, the majority of the absorbed dose was excreted in the urine. The radioactivity in tissues was low (0.2% to 3.6% of the dose), regardless of the dose, route, or species. Disposition of 5-amino-o-cresol in female Wistar Han rats following intravenous (12.5 mg/kg) or gavage (12.5 or 500 mg/kg) administration was similar to that reported by Hedtke et al.^18^ with 94% or 78% or greater, respectively, of the administered dose excreted in urine within 24 hours.^19^ The absorption following dermal application of 12.5 or 37.5 mg/kg in female Wistar Han rats (dose site occluded and oral grooming prevented) was 59% or 35%, respectively, and was similar to the values reported by Hedtke et al.^18^ when the dose site was unprotected.

In F344 rats, following gavage administration of 5-amino-o-cresol, five metabolites were identified in urine (Figure 2).^18^ The major metabolism was by sulfation or glucuronidation of the hydroxyl group. Following intravenous administration, M5 was the predominant metabolite; whereas following gavage administration, more or less equal amounts of M1 through M5 were observed. These results imply that the first-pass hepatic metabolism might be responsible for metabolism of 5-amino-o-cresol to M1, M2, and M4. Goebel et al.^19^ reported three major metabolites, M2, M3, and N-acetylated 5-amino-o-cresol or its sulfate conjugate, M5, following all three routes of administration. However, at the same dose given, N-acetylated 5-amino-o-cresol constituted 66% of the dose following dermal application compared to 32% or 37% following gavage or intravenous administration, respectively. These data imply that following dermal application, N-acetylation of 5-amino-o-cresol represents a first-pass metabolism prior to entering the systemic circulation.

Figure 2

Urinary Metabolites of 5-Amino-o-cresol in Rats

### Humans

Percutaneous absorption of 5-amino-o-cresol in a hair dye under the conditions of usage was studied by Wolfram and Maibach.^20^ Radiolabeled 5-amino-o-cresol was added to a commercial dye containing 0.69% nonradioactive 5-amino-o-cresol; the mixture was applied to the dry hair of three volunteers, worked into the hair mass for 5 to 8 minutes, and rinsed out after an additional 20 minutes. Urine samples were collected for as long as radioactivity was detected, for approximately 144 hours. The total urinary excretion of radioactivity was 0.2% with 50% of that excreted in 24 hours. N-acetylated 5-amino-o-cresol was detected in human keratinocytes in vitro.^21^ In another study, 5-amino-o-cresol metabolism was compared in the human keratinocyte cell line HaCaT and in human skin in vitro.^19^ N-acetylated 5-amino-o-cresol was the only metabolite detected in HaCaT cells and human skin in vitro. Ogiso et al.^22^ reported penetration of 5-amino-o-cresol through the scalp skin is generally greater than penetration through abdominal skin.

Taken together, these studies show that 5-amino-o-cresol passes through skin in small but detectable amounts.

## Toxicity

### Experimental Animals

The Hazardous Substances Data Bank^1^ summarizes the results of several 5-amino-o-cresol studies previously published elsewhere. The acute 5-amino-o-cresol oral LD_50_ values are 3,600 mg/kg for CFY rats and 2,928 and 4,355 mg/kg for female and male Sprague-Dawley rats, respectively. A dermal dose of up to 5 g/kg produced no dermal toxicity in rabbits.

Dietary administration of 5-amino-o-cresol in subchronic toxicity studies in Sprague Dawley rats was conducted at concentrations of 0%, 0.3%, 1%, or 3% for periods of 3 to 6 months.^1^ Significant reductions in body weights occurred in male and female rats fed 3% and in males fed 1%. No significant differences in the concentrations of methemoglobin or triiodothyronine were noted between the high-dose and control rats; however, the total thyroxine and the free thyroxine serum levels were decreased in the high-dose rats. Thyroid glands of the high- and mid-dose rats showed moderate follicular cell hyperplasia and misshapen and small follicles. Exposure to 5-amino-o-cresol produced significant hepatotoxic effects manifested by centrilobular hepatocytomegaly in an unspecified number of test rats and one control female. Mid- and high-dose male rats exhibited a significant dose-dependent increase in serum glutamic pyruvic transaminase activity. Significant dose-dependent decreases in erythrocyte counts, hemoglobin concentrations, and hematocrit values and increases in mean cell volumes occurred in exposed rats. These observations were suggestive of anemia and may have been related to nutritional deficiency.

Sensitization was evaluated in albino guinea pigs receiving a 3% dermal dose applied daily for 3 weeks, 6 days per week [a mixture of Natrosol^®^ 250HR (2.0%), Tween 80 (2.0%), sodium sulfite (0.05%), deionized water (82.95%), and isopropanol (10.0%) was used as the vehicle].^1^ Two weeks after the last dose of 5-amino-o-cresol, a challenge application was made on the opposite untreated flank of each animal. Reactions were scored on a scale of 0 to 4. Four of the 19 guinea pigs had a reaction, with the total point score (for all four animals) of 4. It was concluded that very weak sensitization was produced by 5-amino-o-cresol. Other studies describe 5-amino-o-cresol as nonirritating to the skin and mildly irritating to the eye, based on tests in rabbits.^23^

Immunotoxicity tests of 5-amino-o-cresol in the local lymph node assay in Balb/C mice demonstrated increased proliferation of the draining lymph node cells at concentrations of 5% and 10% applied dermally (4:1 acetone:olive oil vehicle) indicating contact hypersensitization activity of 5-amino-o-cresol.^24^ However, 5-amino-o-cresol did not appear to be an irritant as measured in a dermal irritancy assay. Furthermore, 5-amino-o-cresol did not have significant effects on the percent of mouse ear swelling in a mouse ear swelling test.

### Humans

No epidemiology studies examining the toxicity of 5-amino-o-cresol as a single chemical component in hair dyes have been reported in the literature.

In a modified Draize repeat-insult patch test, two aqueous 2% 5-amino-o-cresol solutions (3% v/v and 10% w/v) were administered to volunteers.^1^ A dose-related increase in dermatitis was observed (1 of 23, not reproduced, versus 2 of 31, 1 reproduced on rechallenge).

## Reproductive and Developmental Toxicity

### Experimental Animals

Groups of 25 female Sprague Dawley rats were fed diets containing 0%, 0.3%, 1%, or 3% 5-amino-o-cresol for 14 weeks, then mated with untreated males.^1^ Feeding was resumed at the same exposure concentrations for the duration of gestation. While no visceral malformations were noted, there were significant increases in the number of rudimentary 14th ribs in the mid- and high-dose animals and a slight increase in the number of full 14th ribs in the fetuses of these dose groups.

In a dominant lethal study of 5-amino-o-cresol, 20 male rats from each dose group were removed from the test diet (0%, 0.3%, 1%, 3%) after 20 weeks and mated to two untreated females each week for 2 weeks.^1^ All males, except one in the mid-dose group, sired at least one litter. No significant dose-related differences were noted in any of the male reproductive parameters studied. The authors concluded that 5-amino-o-cresol produced no adverse effects on reproductive performance and no dominant lethal effect.

### Humans

There are no studies reported in the literature on the reproductive or developmental toxicity of 5-amino-o-cresol in humans.

## Carcinogenicity

### Experimental Animals

There are no studies reported in the literature on carcinogenic effects of 5-amino-o-cresol in experimental animals.

### Humans

There are no epidemiology studies examining the potential carcinogenic effects of 5-amino-o-cresol reported in the literature. The National Cancer Institute (NCI)^8^ has summarized information on the association of hair dye use in general with cancer and points out that there are conflicting results for such studies.

A 2009 review of 247 studies reporting relative risk of hairdresser occupation and cancer at different sites found that there was a higher risk of cancer in this occupation than in the general population.^25^

Hair dye use has been evaluated in a number of cohort studies for its possible association with cancer. The International Agency for Research on Cancer (IARC)^26^ evaluated six European studies of male hairdressers and barbers; some studies showed an increased risk for urinary bladder tumors. IARC concluded that occupation as a hairdresser or barber entails exposures that are probably carcinogenic. However, linkage between personal use of hair dyes and cancer could not be evaluated. Other studies, which investigated association between permanent hair dye use and breast and hematopoietic cancers, yielded largely negative results.^27^

Case control studies conducted in California^28,29^ showed some linkage between permanent hair dye use and bladder cancer in American women. Other population-based studies looked at an association between hair dye use and cancer in women in Nebraska or Connecticut.^30-33^ In these population-based studies of 112 women who were diagnosed with glioma, a 1.7-fold increased risk of glioma was observed in women who had used any hair coloring product (95% confidence interval (CI) = 1.0 to 2.9, 62 cases) and a 2.4-fold risk in those who used permanent hair coloring products (odds ratio (OR) = 2.4, 95% CI = 1.3 to 4.5, 39 cases).^30^ No association was observed with use of nonpermanent (sometimes called temporary or semipermanent) hair coloring products.^30^

A study in Connecticut examined the association between hair dye use and non-Hodgkin’s lymphoma.^33^ A total of 601 histologically confirmed female cases and 717 population-based controls were included in the study. An increased risk of non-Hodgkin’s lymphoma was observed among women who reported use of hair-coloring products before 1980 (OR = 1.3, 95% CI: 1.0 to 1.8). The odds ratios were 2.1 (95% CI: 1.0 to 4.0) for those using darker permanent hair-coloring products for more than 25 years and 1.7 (95% CI: 1.0 to 2.8) for those who had more than 200 applications. Follicular-type, B-cell, and low-grade lymphoma generally showed an increased risk. On the other hand, the authors found no increased risk of non-Hodgkin’s lymphoma overall and by subtype of exposure and disease among women who started using hair-coloring products in 1980 or later.

A population-based, case control study of 385 non-Hodgkin’s lymphoma cases, 70 Hodgkin’s disease cases, 72 multiple myeloma cases, 56 chronic lymphocytic leukemia cases, and 1,432 controls found that hair coloring product use appeared to increase the risk of non-Hodgkin’s lymphoma.^32^ The same study found that the risks were higher among women who used brown, black, or red hair dyes, i.e., colors whose preparation may involve 5-amino-o-cresol.^13^ None of the epidemiological studies found in the literature discussed the specific ingredients (5-amino-o-cresol) contained in the hair dyes.

## Genetic Toxicity

5-Amino-o-cresol was tested for mutagenicity over a dose range of 33 to 6,666 µg/plate in four strains of Salmonella typhimurium (TA97, TA98, TA100, and TA1535) with and without 10% induced male Sprague-Dawley rat or Syrian hamster liver S9 enzymes; it was positive in three of four strains (TA97, TA98, and TA100) in the presence of either species of S9 and negative in TA1535 with or without S9.^34^ Among the three strains that gave positive responses, the strongest mutagenic response (based both on fold-increase and the lowest effective dose) occurred in TA98, a strain that reverts via frame shifting.

In short-term tests for assessment of micronucleated reticulocyte frequencies in blood or bone marrow of male B6C3F1/N mice administered 5-amino-o-cresol (100 to 400 mg/kg per day) via gavage once daily for 3 days, no significant increases were observed.^35^ In addition, no significant changes in the percentage of reticulocytes were seen in these mice, suggesting that 5-amino-o-cresol did not induce bone marrow toxicity over the dose range tested.

## Study Rationale

5-Amino-o-cresol was nominated for study by the NCI because it is a widely used genotoxic hair dye component for which no cancer studies have been reported. These 5-amino-o-cresol studies were conducted by the dermal route to mimic human exposure, and to identify any target organ toxicity by this route of administration.