# Appendix F Chemical Characterization and Dose Formulation Studies

## F.1 Procurement and Characterization

### F.1.1 5-Amino-o-cresol

5-Amino-o-cresol was obtained from Fluka Chemical Company (Buchs, Switzerland) in one lot (385913/1) that was used in the 3-month dermal studies. Identity, purity, and stability analyses were conducted by the analytical chemistry laboratory at Research Triangle Institute (Research Triangle Park, NC) and the study laboratory at Battelle Columbus Operations (Columbus, OH). Karl Fischer titration was performed by Galbraith Laboratories (Knoxville, TN). Reports on analyses performed in support of the 5-amino-o-cresol studies are on file at the National Institute of Environmental Health Sciences.

The test chemical, a beige powder, was identified as 5-amino-o-cresol by the analytical chemistry laboratory and the study laboratory using infrared (IR) spectroscopy; the analytical chemistry laboratory also used proton nuclear magnetic resonance (NMR) spectroscopy, gas chromatography (GC) with mass spectrometry, and melting point determination. All spectra were consistent with the structure of 5-amino-o-cresol, and the mass spectrum and IR spectrum were consistent with the literature spectra.^63^ Representative IR, NMR, and electron ionization mass spectra are presented in Figure F-1, Figure F-2, and Figure F-3, respectively. The melting point was consistent with the melting point reported on the manufacturer’s Certificate of Analysis.

For lot 385913/1, Karl Fischer titration was used to determine the water content of the test chemical. The purity was determined by the analytical chemistry laboratory using GC with flame ionization detection (FID) by systems A and B (Table F-1), and high-performance liquid chromatography (HPLC) with ultraviolet light (UV) detection by system A (Table F-2).

Karl Fischer titration indicated a range of 0.14% to 0.48% water. GC/FID analysis by system A (Table F-1) indicated one major peak with three impurities greater than 0.1% of the total peak area, with a combined total of 0.80% of the total peak area. GC/FID analysis by system B (Table F-1) indicated one major peak and one impurity with an area of 0.37% relative to the total peak area. HPLC/UV by system A (Table F-2) indicated one major peak and no impurities. The overall purity of lot 385913/1 was estimated to be greater than 99%.

Stability studies of the test chemical were performed by the analytical chemistry laboratory using GC/FID by system C (Table F-1). Stability was confirmed for at least 2 weeks for samples stored in sealed amber glass vials at temperatures up to 25°C. To ensure stability, the test chemical was stored in sealed amber glass vials at room temperature (~25°C). Periodic reanalyses of the test chemical were performed by the study laboratory using HPLC/UV by system B (Table F-2); no degradation was observed.

### F.1.2 Ethanol

USP-grade 95% ethanol was obtained from Spectrum Chemical and Laboratory Products (Gardena, CA) in one lot (UO0008) that was used as the vehicle in the 3-month dermal studies. Lot UO0008, a clear liquid, was identified as ethanol by the study laboratory using IR spectroscopy; the IR spectrum was consistent with a literature spectrum of ethanol.^64^

The purity of lot UO0008 was determined by the study laboratory using GC/FID by systems D and E (Table F-1). Analysis by system D indicated there were no impurities greater than 0.1% of the total peak area; analysis by system E indicated no benzene in the vehicle. The overall purity was determined to be greater than 99%.

To ensure stability, lot UO0008 of the vehicle was stored at ambient conditions. Reanalyses of the vehicle were performed by the study laboratory using GC/FID by system D, and no degradation was observed.

## F.2 Preparation and Analysis of Dose Formulations

The dose formulations were prepared by mixing 5-amino-o-cresol with 95% ethanol to give the required concentrations (Table F-3). The dose formulations were stored in amber glass bottles sealed with Teflon^®^-lined lids at room temperature (~25°C) and used within 35 days. The dose formulations were prepared four times during the 3-month studies.

Stability studies of the 4 mg/mL dose formulation were performed by the analytical chemistry laboratory with HPLC/UV using system B (Table F-2). Stability was confirmed for at least 42 days for dose formulations stored in glass containers sealed with Teflon^®^-lined lids, protected from light, at temperatures up to 25°C, and for 3 hours under simulated animal room conditions. A dose simulation (skin paint) stability study was also performed using HPLC/UV by system B. Samples of the 4 mg/mL dose formulation were placed in partially covered Teflon^®^ Petri dishes under a hood; stability was confirmed for at least 5 hours.

The dose formulations were analyzed three times by the study laboratory using HPLC/UV by system B. All 15 dose formulations analyzed for rats and mice were within 10% of the target concentrations (Table F-4). Animal room samples of these dose formulations were also analyzed; all 15 samples for rats and all 15 samples for mice were within 10% of the target concentrations.

Table F-1 Gas Chromatography Systems Used in the Three-month Dermal Studies of 5-Amino-o-cresol^a^

Detection System | Column | Carrier Gas | Oven Temperature Program
System A
Flame ionization | Equity^®^-5, 30 m × 0.32 mm, 0.25 µm film (Supelco, Inc., Bellefonte, PA) | Helium at 1.2 mL/minute | 50°C for 15 minutes, then 10°C/minute to 250°C, held for 25 minutes
System B
Flame ionization | DBTM-624, 30 m × 0.548 mm, 3.0 µm film (J&W Scientific, Folsom, CA) | Helium at 3.9 mL/minute | 40°C for 10 minutes, then 5°C/minute to 200°C, held for 18 minutes
System C
Flame ionization | Equity^®^-5, 30 m × 0.32 mm, 0.25 µm film (Supelco, Inc.) | Helium at 1.0 mL/minute | 40°C for 10 minutes, then 5°C/minute to 200°C, held for 18 minutes
System D
Flame ionization | DB™-WAX, 30 m × 0.53 mm, 1.0 µm film (J&W Scientific) | Helium at 10 mL/minute | 40°C for 5 minutes, then 10°C/minute to 220°C, held for 5 minutes
System E
Flame ionization | Rtx^®^-5, 30 m × 0.53 mm, 1.5 µm film (Restek, Bellefonte, PA) | Helium at 10 mL/minute | 40°C for 3 minutes, then 10°C/minute to 200°C, held for 3 minutes

^a^ The gas chromatographs were manufactured by Hewlett-Packard (Palo Alto, CA).

Table F-2 High-Performance Liquid Chromatography Systems Used in the Three-month Dermal Studies of 5-Amino-o-cresol^a^

Detection System | Column | Solvent System
System A
Ultraviolet (210 nm) light | Atlantis™ dC_18_, 15 cm × 3.9 mm, 5 μm film (Waters-Millipore, Milford, MA) | 20 mM NH_4_H_2_PO_4_ buffer (pH~3.0):methanol (95:5); isocratic, flow rate 1.0 mL/minute
System B
Ultraviolet (210 nm) light | ZORBAX Eclipse XDBTM –C_8_, 250 mm × 4.6 mm, 5.0 μm film (Agilent Technologies, Inc., Santa Clara, CA) | A) 10:90 methanol:water with 20 mM NH_4_H_2_PO_4_ buffer adjusted to pH 2.5 with H_3_PO_4_ B) 90:10 methanol:water with 20 mM NH_4_H_2_PO_4_ buffer adjusted to pH 2.5 with H_3_PO_4_; 100% A for 2 minutes, then linear gradient to 50% A:50% B in 10 minutes, held for 2 minutes, then linear gradient to 100% A in 2 minutes, held 13 minutes; flow rate 1.0 mL/minute

^a^ The high-performance liquid chromatographs were manufactured by Waters Corporation (Milford, MA).

Table F-3 Preparation and Storage of Dose Formulations in the Three-month Dermal Studies of 5-Amino-o-cresol

Three-month Studies
Preparation
Dose formulations were prepared by weighing the appropriate amount of 5-amino-o-cresol into a beaker, then transferring with three 95% ethanol rinses to a calibrated mixing container half-filled with 95% ethanol, diluted to final volume, stirred on a stirplate for 5 minutes or until dissolved; if necessary, sonicated to get into solution.
Chemical Lot Number
385913/1
Maximum Storage Time
35 days
Storage Conditions
The dose formulations were stored in amber glass vials sealed with Teflon^®^-lined lids at 25°C.
Study Laboratory
Battelle Columbus Operations (Columbus, OH)

Table F-4 Results of Analyses of Dose Formulations Administered to Rats and Mice in the Three-month Dermal Studies of 5-Amino-o-cresol

Date Prepared | Date Analyzed | Target Concentration (mg/mL) | Determined Concentration^a^ (mg/mL) | Difference from Target (%)
Rats
April 26, 2006 | May 1–2, 2006 | 4 | 3.889 | −3
| | 8 | 7.806 | −2
| | 16 | 15.65 | −2
| | 32 | 31.05 | −3
| | 64 | 60.88 | −5
| May 31–June 1, 2006^b^ | 4 | 3.894 | −3
| | 8 | 7.843 | −2
| | 16 | 15.61 | −2
| | 32 | 31.44 | −2
| | 64 | 61.68 | −4
May 19, 2006 | May 22–23, 2006 | 4 | 3.871 | −3
| | 8 | 7.593 | −5
| | 16 | 15.20 | −5
| | 32 | 29.76 | −7
May 24, 2006 | May 24, 2006 | 64 | 63.94 | 0
| June 26–27, 2006^b^ | 4 | 3.914 | −2
| | 8 | 7.834 | −2
| | 16 | 15.63 | −2
| | 32 | 31.15 | −3
| | 64 | 61.90 | −3
July 11, 2006 | July 12–13, 2006 | 4 | 3.784 | −5
| | 8 | 7.401 | −8
| | 16 | 15.23 | −5
| | 32 | 29.13 | −9
| | 64 | 59.37 | −7
| September 6–7, 2006^b^ | 4 | 3.814 | −5
| | 8 | 7.660 | −4
| | 16 | 15.48 | −3
| | 32 | 29.63 | −7
| | 64 | 61.41 | −4
Mice
April 26, 2006 | May 1–2, 2006 | 4 | 3.889 | −3
| | 8 | 7.806 | −2
| | 16 | 15.65 | −2
| | 32 | 31.05 | −3
| | 64 | 60.88 | −5
| May 31–June 1, 2006^c^ | 4 | 3.871 | −3
| | 8 | 7.715 | −4
| | 16 | 15.57 | −3
| | 32 | 31.52 | −2
| | 64 | 61.23 | −4
May 19, 2006 | May 22–23, 2006 | 4 | 3.871 | −3
| | 8 | 7.593 | −5
| | 16 | 15.20 | −5
| | 32 | 29.76 | −7
May 24, 2006 | May 24, 2006 | 64 | 63.94 | 0
May 19, 2006 | June 26–27, 2006^c^ | 4 | 3.854 | −4
| | 8 | 7.759 | −3
| | 16 | 15.57 | −3
| | 32 | 30.13 | −6
| | 64 | 61.15 | −5
July 11, 2006 | July 12–13, 2006 | 4 | 3.784 | −5
| | 8 | 7.401 | −8
| | 16 | 15.23 | −5
| | 32 | 29.13 | −9
| | 64 | 59.37 | −7
| August 11–12, 2006^c^ | 4 | 3.802 | −5
| | 8 | 7.764 | −3
| | 16 | 15.75 | −2
| | 32 | 31.33 | −2
| | 64 | 62.86 | −2

^a^ Results of duplicate analyses. For rats, dosing volume = 0.5 mL/kg; 4 mg/mL = 2 mg/kg, 8 mg/mL = 4 mg/kg, 16 mg/mL = 8 mg/kg, 32 mg/mL = 16 mg/kg, 64 mg/mL = 32 mg/kg. For mice, dosing volume = 2 mL/kg; 4 mg/mL = 8 mg/kg, 8 mg/mL = 16 mg/kg, 16 mg/mL = 32 mg/kg, 32 mg/mL = 64 mg/kg, 64 mg/mL = 128 mg/kg.

^b^ Animal room samples for rats.

^c^ Animal room samples for mice.

Figure F-1

Infrared Absorption Spectrum of 5-Amino-o-cresol

Figure F-2

Proton Nuclear Magnetic Resonance Spectrum of 5-Amino-o-cresol

Figure F-3

Electron Ionization Mass Spectrum of 5-Amino-o-cresol