# Appendix E Genetic Toxicology

Table E-1 Mutagenicity of 5-Amino-o-cresol in Salmonella typhimurium^a^

Strain | Dose (μg/Plate) | Without S9 | Without S9 | With 10% Hamster S9 | With 10% Hamster S9 | With 10% Rat S9 | With 10% Rat S9
TA100 | 0 | 89 ± 10 | 74 ± 10 | 86 ± 3 | 71 ± 3 | 83 ± 4 | 72 ± 1
| 33 | 83 ± 5 | 78 ± 5 | | 78 ± 6 | | 79 ± 5
| 100 | 80 ± 7 | 73 ± 2 | 85 ± 9 | 83 ± 5 | 76 ± 1 | 85 ± 5
| 333 | 94 ± 5 | 89 ± 2 | 116 ± 7 | 107 ± 6 | 94 ± 6 | 107 ± 6
| 1,000 | 105 ± 3 | 91 ± 8 | 213 ± 12 | 205 ± 9 | 137 ± 10 | 193 ± 10
| 2,000 | 112 ± 4
| 3,333 | | Toxic | 476 ± 29 | 369 ± 13 | 210 ± 17 | 263 ± 13
| 6,666 | | | 166 ± 6^b^ | | 317 ± 2
Trial summary | | Negative | Negative | Positive | Positive | Positive | Positive
Positive control^c^ | | 241 ± 5 | 337 ± 20 | 181 ± 12 | 308 ± 4 | 862 ± 57 | 502 ± 44
TA97 | 0 | 93 ± 4 | | 110 ± 5 | 131 ± 9 | 123 ± 9 | 76 ± 4
| 33 | 85 ± 2 | | | 129 ± 4 | | 94 ± 4
| 100 | 97 ± 9 | | 117 ± 3 | 125 ± 7 | 158 ± 2 | 100 ± 5
| 333 | 106 ± 14 | | 208 ± 8 | 180 ± 10 | 207 ± 14 | 128 ± 4
| 1,000 | 102 ± 7 | | 443 ± 6 | 391 ± 19 | 303 ± 10 | 303 ± 25
| 2,000 | 110 ± 8^b^
| 3,333 | | | 949 ± 21 | 824 ± 21 | 792 ± 18 | 432 ± 31
| 6,666 | | | 116 ± 15^b^ | | 277 ± 62
Trial summary | | Negative | – | Positive | Positive | Positive | Positive
Positive control | | 147 ± 3 | – | 548 ± 21 | 664 ± 37 | 1,343 ± 64 | 1,277 ± 107^d^
TA98 | 0 | 17 ± 1 | 16 ± 1 | 27 ± 3 | 35 ± 2 | 33 ± 2 | 27 ± 2
| 33 | 18 ± 1 | 21 ± 1 | | 34 ± 4 | | 39 ± 2
| 100 | 20 ± 3 | 17 ± 1 | 60 ± 10 | 59 ± 6 | 64 ± 3 | 55 ± 6
| 333 | 20 ± 3 | 22 ± 2 | 216 ± 21 | 179 ± 17 | 191 ± 4 | 180 ± 8
| 1,000 | 23 ± 5 | 21 ± 1 | 984 ± 13 | 824 ± 25 | 797 ± 4 | 779 ± 20
| 2,000 | 41 ± 5
| 3,333 | | 21 ± 3 | 2,011 ± 30 | 1,703 ± 79 | 1,159 ± 101 | 1,121 ± 82
| 6,666 | | | 848 ± 38 | | 234 ± 39
Trial summary | | Equivocal | Negative | Positive | Positive | Positive | Positive
Positive control | | 218 ± 7 | 180 ± 9 | 121 ± 2 | 109 ± 9 | 262 ± 7 | 205 ± 9
TA1535 | 0 | 24 ± 1 | 19 ± 3 | 9 ± 2 | 13 ± 3 | 12 ± 1 | 9 ± 1
| 33 | 24 ± 5 | 22 ± 4 | | 9 ± 2 | | 10 ± 1
| 100 | 20 ± 2 | 19 ± 3 | 10 ± 2 | 10 ± 1 | 8 ± 1 | 8 ± 1
| 333 | 21 ± 3 | 20 ± 1 | 13 ± 1 | 15 ± 1 | 7 ± 0 | 11 ± 1
| 1,000 | 23 ± 3 | 14 ± 2 | 11 ± 3 | 16 ± 3 | 8 ± 0 | 8 ± 2
| 2,000 | 15 ± 2
| 3,333 | | Toxic | 11 ± 2 | 11 ± 1 | 13 ± 1 | 11 ± 3
| 6,666 | | | 9 ± 2^b^ | | 7 ± 1
Trial summary | | Negative | Negative | Negative | Negative | Negative | Negative
Positive control | | 130 ± 5 | 173 ± 10 | 35 ± 5 | 46 ± 2 | 211 ± 12 | 170 ± 4

^a^ Study was performed at BioReliance Corporation. Data are presented as revertants/plate (mean ± standard error) from three plates. 0 μg/plate was the solvent control. The detailed protocol and these data are presented by Zeiger et al.^34^

^b^ Slight toxicity.

^c^ The positive controls in the absence of metabolic activation were sodium azide (TA100 and TA1535), 9-aminoacridine (TA97), and 4-nitro-o-phenylenediamine (TA98). The positive control for metabolic activation with all strains was 2-aminoanthracene.

^d^ Contamination.

Table E-2 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Mice Following Dermal Application of 5-Amino-o-cresol for Three Months^a^

| Dose (mg/kg) | Number of Mice with Erythrocytes Scored | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs^b^ (%)
Male
Ethanol^d^ | 0 | 5 | 1.50 ± 0.35 | | 3.52 ± 0.20
5-Amino-o-cresol | 8 | 5 | 1.30 ± 0.25 | 0.6474 | 4.12 ± 0.18
| 16 | 5 | 1.00 ± 0.35 | 0.8415 | 3.48 ± 0.22
| 32 | 5 | 1.10 ± 0.29 | 0.7838 | 3.52 ± 0.07
| 64 | 5 | 1.30 ± 0.60 | 0.6474 | 3.36 ± 0.22
| 128 | 5 | 1.60 ± 0.48 | 0.4287 | 3.52 ± 0.18
| | | P = 0.241^e^
Female
Ethanol | 0 | 5 | 2.10 ± 0.24 | | 3.64 ± 0.14
5-Amino-o-cresol | 8 | 5 | 1.00 ± 0.42 | 0.9760 | 3.44 ± 0.23
| 16 | 5 | 1.30 ± 0.20 | 0.9151 | 3.64 ± 0.28
| 32 | 5 | 1.90 ± 0.37 | 0.6242 | 3.14 ± 0.11
| 64 | 5 | 0.80 ± 0.20 | 0.9921 | 3.40 ± 0.29
| 128 | 5 | 1.20 ± 0.37 | 0.9416 | 3.56 ± 0.08
| | | P = 0.888

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Witt et al.^35^ NCE = normochromatic erythrocyte; PCE = polychromatic erythrocyte.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the vehicle control group; dosed group values are significant at P ≤ 0.005.

^d^ Vehicle control.

^e^ Significance of micronucleated NCEs/1,000 NCEs tested by the one-tailed Cochran-Armitage trend test; significant at P ≤ 0.025.

Table E-3 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Male Mice Following Administration of 5-Amino-o-cresol by Gavage for Three Days^a^

Dose (mg/kg) | Number of Mice with Erythrocytes Scored | Micronucleated PCEs/1,000 PCEs^b^ | P Value^c^ | Micronucleated PCEs/1,000 PCEs^b^ | P Value^c^ | PCEs^b^ (%) | P Value^c^
Corn oil^d^
0 | 5 | 2.44 ± 0.18 | | 1.59 ± 0.05 | | 1.695 ± 0.06
5-Amino-o-cresol
100 | 5 | 2.41 ± 0.19 | 0.6870 | 1.54 ± 0.03 | 0.7323 | 1.720 ± 0.07 | 1.000
200 | 5 | 2.06 ± 0.24 | 0.7732 | 1.52 ± 0.05 | 0.8137 | 1.633 ± 0.11 | 0.654
400 | 5 | 2.34 ± 0.16 | 0.7669 | 1.57 ± 0.03 | 0.7311 | 1.418 ± 0.07 | 0.026
| | P = 0.696^e^ | | P = 0.562 | | P = 0.009
Cyclophosphamide^f^
50 | 5 | 28.0 ± 1.09 | 0.0000 | 1.91 ± 0.03 | 0.0000 | 0.149 ± 0.01 | 0.000

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Shelby et al.^51^ and Witt et al.^35^ NCE = normochromatic erythrocyte; PCE = polychromatic erythrocyte.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the vehicle control group; significant at P ≤ 0.025 by Williams’ test.

^d^ Vehicle control.

^e^ Dose-related trend; significant at P ≤ 0.025 by linear regression.

^f^ Positive control.

Table E-4 Induction of Micronuclei in Bone Marrow Erythrocytes of Male Mice Following Administration of 5-Amino-o-cresol by Gavage for Three Days^a^

| Dose (mg/kg) | Number of Mice with Erythrocytes Scored | Micronucleated PCEs/1,000 PCEs^b^ | P Value^c^ | PCEs^b^ (%)
Trial 1
Corn oil^d^ | 0 | 5 | 1.10 ± 0.51 | | 68.80 ± 1.55
5-Amino-o-cresol | 100 | 5 | 2.78 ± 0.60 | 0.0039 | 62.30 ± 4.39
| 200 | 5 | 1.60 ± 0.56 | 0.1678 | 65.20 ± 2.08
| 400 | 5 | 2.20 ± 0.46 | 0.0277 | 66.50 ± 2.95
| | | P = 0.137^e^
Cyclophosphamide^f^ | 50 | | 39.90 ± 4.46 | 0.0000 | 27.30 ± 2.31
Trial 2
Corn oil | 0 | 5 | 3.00 ± 0.74 | | 63.10 ± 2.51
5-Amino-o-cresol | 50 | 5 | 2.10 ± 0.58 | 0.8965 | 57.10 ± 4.15
| 100 | 5 | 2.90 ± 0.48 | 0.5519 | 64.60 ± 3.07
| 200 | 5 | 2.10 ± 0.37 | 0.8965 | 61.40 ± 4.79
| 400 | 4 | 2.25 ± 0.32 | 0.8339 | 64.75 ± 3.71
| | | P = 0.805
Cyclophosphamide | 50 | | 42.50 ± 1.54 | 0.0000 | 26.00 ± 3.84

^a^ Study was performed at ILS, Inc. The detailed protocol and these data are presented by Witt et al.^35^ PCE = polychromatic erythrocyte.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the vehicle control group; dosed group values are significant at P ≤ 0.008 (trial 1) or P ≤ 0.006 (trial 2); positive control values are significant at P ≤ 0.025.

^d^ Vehicle control.

^e^ Significance of micronucleated PCEs/1,000 PCEs tested by the one-tailed Cochran-Armitage trend test; significant at P ≤ 0.025.

^f^ Positive control.