# Appendix D Reproductive Tissue Evaluations and Estrous Cycle Characterization

Table D-1 Summary of Reproductive Tissue Evaluations for Male Rats in the Three-month Dermal Study of 5-Amino-o-cresol^a^

| Vehicle Control | 8 mg/kg | 16 mg/kg | 32 mg/kg
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy body wt | 324 ± 6 | 339 ± 5 | 333 ± 7 | 333 ± 4
L. Cauda epididymis | 0.1387 ± 0.0045 | 0.1358 ± 0.0023 | 0.1387 ± 0.0039 | 0.1426 ± 0.0046
L. Epididymis | 0.4109 ± 0.0080 | 0.4094 ± 0.0054 | 0.4121 ± 0.0048 | 0.4135 ± 0.0055
L. Testis | 1.4154 ± 0.0148 | 1.4127 ± 0.0137 | 1.4519 ± 0.0156 | 1.4611 ± 0.0165
Spermatid measurements
Spermatid heads (10^6^/g testis) | 157.0 ± 4.6 | 157.0 ± 5.4 | 160.0 ± 5.1 | 153.1 ± 5.3
Spermatid heads (10^6^/testis) | 187.4 ± 6.1 | 185.9 ± 5.2 | 196.1 ± 6.5 | 183.8 ± 4.3
Epididymal spermatozoal measurements
Sperm motility (%) | 84 ± 0 | 84 ± 0 | 85 ± 1 | 85 ± 0
Sperm (10^6^/g cauda epididymis) | 789.1 ± 48.3 | 744.2 ± 84.7 | 811.9 ± 36.9 | 787.7 ± 30.2
Sperm (10^6^/cauda epididymis) | 109.3 ± 7.1 | 100.8 ± 11.1 | 112.1 ± 4.8 | 113.0 ± 6.9

^a^ Data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test (body and tissue weights) or Dunn’s test (spermatid and epididymal spermatozoal measurements).

Table D-2 Estrous Cycle Characterization for Female Rats in the Three-month Dermal Study of 5-Amino-o-cresol^a^

| Vehicle Control | 8 mg/kg | 16 mg/kg | 32 mg/kg
Number weighed at necropsy | 10 | 10 | 10 | 10
Necropsy body wt (g) | 186 ± 3 | 185 ± 3 | 187 ± 4 | 184 ± 3
Proportion of regular cycling females^b^ | 10/10 | 9/10 | 10/10 | 10/10
Estrous cycle length (days) | 5.0 ± 0.00 | 5.0 ± 0.05 | 5.0 ± 0.00 | 5.0 ± 0.00
Estrous stages (% of cycle)
Diestrus | 58.8 | 62.5 | 60.0 | 60.0
Proestrus | 13.8 | 15.0 | 17.5 | 18.8
Estrus | 26.9 | 21.9 | 21.3 | 20.6
Metestrus | 0.6 | 0.6 | 1.3 | 0.6

^a^ Necropsy body weights and estrous cycle length data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test (body weights) or Dunn’s test (estrous cycle length). By multivariate analysis of variance, dosed females do not differ significantly from the vehicle control females in the relative length of time spent in the estrous stages. Tests for equality of transition probability matrices among all groups and between the vehicle control group and each dosed group indicated no significant differences in the probability of an altered cycle for any treated group compared to the vehicle controls.

^b^ Number of females with a regular cycle/number of females cycling.

Table D-3 Summary of Reproductive Tissue Evaluations for Male Mice in the Three-month Dermal Study of 5-Amino-o-cresol^a^

| Vehicle Control | 32 mg/kg | 64 mg/kg | 128 mg/kg
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy body wt | 41.8 ± 0.8 | 42.7 ± 1.1 | 42.1 ± 1.0 | 42.5 ± 1.1
L. Cauda epididymis | 0.0145 ± 0.0004 | 0.0137 ± 0.0004 | 0.0144 ± 0.0006 | 0.0144 ± 0.0006
L. Epididymis | 0.0422 ± 0.0006 | 0.0417 ± 0.0008 | 0.0419 ± 0.0011 | 0.0418 ± 0.0007
L. Testis | 0.1147 ± 0.0018 | 0.1150 ± 0.0021 | 0.1120 ± 0.0029 | 0.1112 ± 0.0027
Spermatid measurements
Spermatid heads (10^6^/g testis) | 233.4 ± 7.8 | 225.6 ± 8.0 | 220.1 ± 8.4 | 228.2 ± 7.3
Spermatid heads (10^6^/testis) | 23.2 ± 0.8 | 22.0 ± 1.1 | 21.1 ± 1.2 | 20.7 ± 0.9
Epididymal spermatozoal measurements
Sperm motility (%) | 87 ± 1 | 88 ± 0 | 88 ± 0 | 88 ± 1
Sperm (10^6^/g cauda epididymis) | 1,440.3 ± 82.6 | 1,451.0 ± 140.5 | 1,192.7 ± 98.4 | 1,383.7 ± 147.1
Sperm (10^6^/cauda epididymis) | 20.8 ± 1.2 | 19.7 ± 1.7 | 17.0 ± 1.3 | 19.6 ± 1.9

^a^ Data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test (body and tissue weights) or Dunn’s test (spermatid and epididymal spermatozoal measurements).

Table D-4 Estrous Cycle Characterization for Female Mice in the Three-month Dermal Study of 5-Amino-o-cresol^a^

| Vehicle Control | 32 mg/kg | 64 mg/kg | 128 mg/kg
Number weighed at necropsy | 10 | 9 | 10 | 10
Necropsy body wt (g) | 37.6 ± 1.0 | 39.0 ± 1.5 | 36.4 ± 1.7 | 36.3 ± 1.1
Proportion of regular cycling females^b^ | 9/10 | 9/9 | 9/10 | 8/10
Estrous cycle length (days) | 4.4 ± 0.13 | 4.9 ± 0.10 | 4.7 ± 0.19 | 4.8 ± 0.24
Estrous stages (% of cycle)
Diestrus | 31.9 | 38.9 | 35.6 | 36.9
Proestrus | 0.0 | 0.7 | 0.0 | 0.0
Estrus | 45.6 | 40.3 | 43.1 | 41.9
Metestrus | 22.5 | 20.1 | 21.3 | 21.3

^a^ Necropsy body weights and estrous cycle length data are presented as mean ± standard error. Differences from the vehicle control group are not significant by Dunnett’s test (body weight) or Dunn’s test (estrous cycle length). By multivariate analysis of variance, dosed females do not differ significantly from the vehicle control females in the relative length of time spent in the estrous stages. Tests for equality of transition probability matrices among all groups and between the vehicle control group and each dosed group indicated no significant differences in the probability of an altered cycle for any treated group compared to the vehicle controls.

^b^ Number of females with a regular cycle/number of females cycling.