# Appendix C Organ Weights and Organ-Weight-to-Body-Weight Ratios

Table C-1 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Rats in the Three-month Dermal Study of 5-Amino-o-cresol^a^

| Vehicle Control | 2 mg/kg | 4 mg/kg | 8 mg/kg | 16 mg/kg | 32 mg/kg
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Necropsy body wt | 324 ± 6 | 324 ± 5 | 329 ± 7 | 339 ± 5 | 333 ± 7 | 333 ± 4
Heart
Absolute | 0.95 ± 0.02 | 0.95 ± 0.02 | 0.98 ± 0.02 | 1.02 ± 0.03* | 0.99 ± 0.02 | 0.98 ± 0.01
Relative | 2.93 ± 0.05 | 2.94 ± 0.04 | 2.98 ± 0.04 | 3.02 ± 0.08 | 2.98 ± 0.04 | 2.94 ± 0.04
R. Kidney
Absolute | 1.07 ± 0.03 | 1.05 ± 0.01 | 1.10 ± 0.04 | 1.13 ± 0.02 | 1.09 ± 0.02 | 1.12 ± 0.02
Relative | 3.30 ± 0.06 | 3.23 ± 0.05 | 3.35 ± 0.05 | 3.34 ± 0.05 | 3.27 ± 0.04 | 3.37 ± 0.03
Liver
Absolute | 12.46 ± 0.36 | 12.69 ± 0.33 | 12.99 ± 0.35 | 13.90 ± 0.29** | 13.12 ± 0.24 | 13.34 ± 0.25
Relative | 38.39 ± 0.53 | 39.12 ± 0.84 | 39.52 ± 0.49 | 41.02 ± 0.62* | 39.44 ± 0.44 | 40.04 ± 0.69
Lung
Absolute | 1.87 ± 0.09 | 2.00 ± 0.08 | 2.04 ± 0.10 | 2.01 ± 0.06 | 2.08 ± 0.11 | 2.00 ± 0.07
Relative | 5.76 ± 0.25 | 6.16 ± 0.20 | 6.22 ± 0.28 | 5.95 ± 0.18 | 6.25 ± 0.29 | 6.00 ± 0.22
R. Testis
Absolute | 1.385 ± 0.025 | 1.375 ± 0.020 | 1.397 ± 0.015 | 1.375 ± 0.020 | 1.393 ± 0.019 | 0.410 ± 0.018
Relative | 4.279 ± 0.079 | 4.250 ± 0.104 | 4.264 ± 0.067 | 4.061 ± 0.055 | 4.197 ± 0.092 | 4.233 ± 0.051
Thymus
Absolute | 0.346 ± 0.012 | 0.325 ± 0.006 | 0.357 ± 0.014 | 0.368 ± 0.017 | 0.339 ± 0.016 | 0.334 ± 0.010
Relative | 1.070 ± 0.041 | 1.001 ± 0.016 | 1.085 ± 0.034 | 1.089 ± 0.052 | 1.013 ± 0.031 | 1.001 ± 0.026
Female
Necropsy body wt | 186 ± 3 | 188 ± 4 | 192 ± 3 | 185 ± 3 | 187 ± 4 | 184 ± 3
Heart
Absolute | 0.67 ± 0.01 | 0.67 ± 0.02 | 0.71 ± 0.02 | 0.66 ± 0.01 | 0.67 ± 0.02 | 0.66 ± 0.01
Relative | 3.62 ± 0.06 | 3.56 ± 0.06 | 3.68 ± 0.11 | 3.57 ± 0.07 | 3.60 ± 0.05 | 3.60 ± 0.10
R. Kidney
Absolute | 0.68 ± 0.01 | 0.69 ± 0.02 | 0.67 ± 0.01 | 0.67 ± 0.01 | 0.68 ± 0.02 | 0.66 ± 0.01
Relative | 3.68 ± 0.04 | 3.66 ± 0.06 | 3.50 ± 0.04 | 3.64 ± 0.05 | 3.64 ± 0.06 | 3.61 ± 0.06
Liver
Absolute | 7.04 ± 0.12 | 7.10 ± 0.22 | 7.19 ± 0.20 | 6.96 ± 0.13 | 6.99 ± 0.23 | 6.81 ± 0.18
Relative | 37.90 ± 0.37 | 37.82 ± 0.77 | 37.45 ± 0.79 | 37.62 ± 0.42 | 37.39 ± 0.67 | 37.11 ± 0.92
Lung
Absolute | 1.46 ± 0.06 | 1.37 ± 0.06 | 1.53 ± 0.07 | 1.40 ± 0.04 | 1.37 ± 0.04 | 1.40 ± 0.10
Relative | 7.83 ± 0.28 | 7.29 ± 0.24 | 8.00 ± 0.41 | 7.59 ± 0.21 | 7.36 ± 0.26 | 7.64 ± 0.56
Thymus
Absolute | 0.257 ± 0.007 | 0.270 ± 0.013 | 0.282 ± 0.012 | 0.258 ± 0.010 | 0.271 ± 0.008 | 0.261 ± 0.009
Relative | 1.387 ± 0.044 | 1.436 ± 0.058 | 1.471 ± 0.058 | 1.392 ± 0.040 | 1.456 ± 0.044 | 1.417 ± 0.038

* Significantly different (P ≤ 0.05) from the vehicle control group by Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Table C-2 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice in the Three-month Dermal Study of 5-Amino-o-cresol^a^

| Vehicle Control | 8 mg/kg | 16 mg/kg | 32 mg/kg | 64 mg/kg | 128 mg/kg
Male
n | 10 | 10 | 10 | 10 | 10 | 10
Necropsy body wt | 41.8 ± 0.8 | 41.1 ± 0.9 | 42.3 ± 0.7 | 42.7 ± 1.1 | 42.1 ± 1.0 | 42.5 ± 1.1
Heart
Absolute | 0.19 ± 0.01 | 0.20 ± 0.01 | 0.21 ± 0.01 | 0.21 ± 0.01 | 0.19 ± 0.01 | 0.19 ± 0.01
Relative | 4.62 ± 0.17 | 4.96 ± 0.09 | 4.85 ± 0.18 | 4.78 ± 0.24 | 4.54 ± 0.14 | 4.46 ± 0.21
R. Kidney
Absolute | 0.31 ± 0.01 | 0.30 ± 0.01 | 0.31 ± 0.00 | 0.31 ± 0.01 | 0.32 ± 0.01 | 0.30 ± 0.01
Relative | 7.34 ± 0.21 | 7.37 ± 0.14 | 7.23 ± 0.09 | 7.26 ± 0.11 | 7.53 ± 0.11 | 7.04 ± 0.19
Liver
Absolute | 1.92 ± 0.06 | 1.85 ± 0.08 | 1.92 ± 0.05 | 2.03 ± 0.08 | 2.03 ± 0.09 | 2.00 ± 0.09
Relative | 45.84 ± 0.84 | 44.68 ± 1.07 | 45.26 ± 0.79 | 47.39 ± 0.79 | 48.17 ± 1.09 | 47.04 ± 1.06
Lung
Absolute | 0.28 ± 0.02 | 0.26 ± 0.01 | 0.26 ± 0.02 | 0.28 ± 0.02 | 0.25 ± 0.01 | 0.25 ± 0.01
Relative | 6.69 ± 0.55 | 6.24 ± 0.37 | 6.22 ± 0.33 | 6.57 ± 0.31 | 6.04 ± 0.36 | 5.85 ± 0.25
R. Testis
Absolute | 0.119 ± 0.002 | 0.123 ± 0.002 | 0.120 ± 0.003 | 0.123 ± 0.003 | 0.118 ± 0.005 | 0.118 ± 0.002
Relative | 2.850 ± 0.064 | 3.006 ± 0.058 | 2.839 ± 0.081 | 2.884 ± 0.070 | 2.799 ± 0.087 | 2.796 ± 0.075
Thymus
Absolute | 0.071 ± 0.007 | 0.065 ± 0.004 | 0.065 ± 0.005 | 0.074 ± 0.003 | 0.066 ± 0.004 | 0.067 ± 0.005
Relative | 1.686 ± 0.158 | 1.585 ± 0.111 | 1.520 ± 0.107 | 1.726 ± 0.078 | 1.581 ± 0.097 | 1.571 ± 0.098
Female
n | 10 | 10 | 9 | 10 | 10 | 10
Necropsy body wt | 37.6 ± 1.0 | 37.7 ± 1.6 | 38.8 ± 1.1 | 39.0 ± 1.5 | 36.4 ± 1.7 | 36.3 ± 1.1
Heart
Absolute | 0.18 ± 0.01 | 0.18 ± 0.01 | 0.20 ± 0.01 | 0.18 ± 0.00 | 0.18 ± 0.01 | 0.17 ± 0.01
Relative | 4.75 ± 0.26 | 4.69 ± 0.19 | 5.13 ± 0.23 | 4.61 ± 0.18 | 5.12 ± 0.34 | 4.58 ± 0.25
R. Kidney
Absolute | 0.20 ± 0.00 | 0.20 ± 0.01 | 0.20 ± 0.00 | 0.20 ± 0.00 | 0.19 ± 0.01 | 0.19 ± 0.00
Relative | 5.39 ± 0.17 | 5.32 ± 0.19 | 5.25 ± 0.12 | 5.16 ± 0.19 | 5.08 ± 0.39 | 5.34 ± 0.15
Liver
Absolute | 1.62 ± 0.02 | 1.60 ± 0.05 | 1.64 ± 0.04 | 1.64 ± 0.05 | 1.61 ± 0.04 | 1.57 ± 0.03
Relative | 43.25 ± 0.72 | 42.67 ± 0.98 | 42.27 ± 0.69 | 42.22 ± 0.80 | 44.63 ± 1.26 | 43.28 ± 0.86
Lung
Absolute | 0.27 ± 0.02 | 0.29 ± 0.02 | 0.29 ± 0.02 | 0.28 ± 0.01 | 0.27 ± 0.01 | 0.27 ± 0.01
Relative | 7.19 ± 0.54 | 7.59 ± 0.45 | 7.63 ± 0.45 | 7.36 ± 0.28 | 7.60 ± 0.58 | 7.43 ± 0.41
Thymus
Absolute | 0.075 ± 0.005 | 0.068 ± 0.004 | 0.070 ± 0.005 | 0.067 ± 0.004 | 0.065 ± 0.003 | 0.068 ± 0.005
Relative | 1.984 ± 0.100 | 1.807 ± 0.108 | 1.801 ± 0.098 | 1.730 ± 0.081 | 1.786 ± 0.067 | 1.852 ± 0.106

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error). Differences from the vehicle control group were not significant by Dunnett’s test.