# Appendix B Clinical Pathology Results

Table B-1 Hematology and Clinical Chemistry Data for Rats in the Three-month Dermal Study of 5-Amino-o-cresol^a^

| Vehicle Control | 2 mg/kg | 4 mg/kg | 8 mg/kg | 16 mg/kg | 32 mg/kg
Male
Hematology
n
Day 4 | 9 | 10 | 10 | 9 | 9 | 10
Day 23 | 10 | 10 | 10 | 10 | 10 | 10
Week 14 | 9 | 9 | 10 | 9 | 8 | 9
Hematocrit (%)
Day 4 | 43.4 ± 0.4 | 43.7 ± 0.4 | 43.2 ± 0.5 | 43.7 ± 0.7 | 43.6 ± 0.6 | 42.9 ± 0.3
Day 23 | 43.4 ± 0.5 | 43.5 ± 0.3 | 42.4 ± 0.4 | 42.5 ± 0.3 | 43.5 ± 0.7 | 41.8 ± 0.5
Week 14 | 46.5 ± 0.5 | 47.2 ± 0.3 | 46.4 ± 0.5 | 45.8 ± 0.3 | 47.7 ± 0.5 | 46.1 ± 0.5
Hemoglobin (g/dL)
Day 4 | 13.8 ± 0.2 | 13.7 ± 0.1 | 13.6 ± 0.2 | 13.9 ± 0.2 | 13.7 ± 0.2 | 13.6 ± 0.1
Day 23 | 14.1 ± 0.2 | 14.1 ± 0.1 | 13.8 ± 0.1 | 14.1 ± 0.2 | 14.2 ± 0.2 | 13.7 ± 0.2
Week 14 | 15.5 ± 0.2 | 15.6 ± 0.1 | 15.4 ± 0.1 | 15.3 ± 0.1 | 15.9 ± 0.1 | 15.4 ± 0.2
Erythrocytes (10^6^/μL)
Day 4 | 7.17 ± 0.06 | 7.26 ± 0.06 | 7.19 ± 0.10 | 7.27 ± 0.11 | 7.22 ± 0.11 | 7.15 ± 0.06
Day 23 | 7.68 ± 0.07 | 7.70 ± 0.06 | 7.61 ± 0.08 | 7.58 ± 0.05 | 7.76 ± 0.11 | 7.48 ± 0.11
Week 14 | 9.46 ± 0.09 | 9.52 ± 0.06 | 9.46 ± 0.09 | 9.46 ± 0.06 | 9.68 ± 0.07 | 9.48 ± 0.09
Reticulocytes (10^3^/μL)
Day 4 | 651 ± 18 | 640 ± 19 | 653 ± 11 | 665 ± 7 | 686 ± 15 | 652 ± 22
Day 23 | 323 ± 12 | 290 ± 9 | 298 ± 12 | 307 ± 13 | 298 ± 8 | 292 ± 7
Week 14 | 208 ± 8 | 192 ± 9 | 194 ± 6 | 188 ± 5 | 207 ± 6 | 199 ± 6
Mean cell volume (fL)
Day 4 | 60.6 ± 0.2 | 60.2 ± 0.2 | 60.1 ± 0.2 | 60.2 ± 0.3 | 60.3 ± 0.2 | 60.0 ± 0.3
Day 23 | 56.5 ± 0.2 | 56.4 ± 0.2 | 55.7 ± 0.2 | 56.0 ± 0.3 | 56.0 ± 0.3 | 55.8 ± 0.2
Week 14 | 49.1 ± 0.2 | 49.6 ± 0.4 | 49.1 ± 0.3 | 48.4 ± 0.3 | 49.2 ± 0.3 | 48.6 ± 0.2
Mean cell hemoglobin (pg)
Day 4 | 19.2 ± 0.1 | 18.9 ± 0.1 | 19.0 ± 0.1 | 19.1 ± 0.2 | 19.0 ± 0.1 | 19.1 ± 0.1
Day 23 | 18.3 ± 0.1 | 18.3 ± 0.1 | 18.2 ± 0.1 | 18.6 ± 0.1 | 18.3 ± 0.1 | 18.3 ± 0.1
Week 14 | 16.4 ± 0.1 | 16.4 ± 0.1 | 16.3 ± 0.1 | 16.1 ± 0.1 | 16.4 ± 0.1 | 16.2 ± 0.1
Mean cell hemoglobin concentration (g/dL)
Day 4 | 31.7 ± 0.2 | 31.4 ± 0.2 | 31.5 ± 0.1 | 31.8 ± 0.1 | 31.5 ± 0.2 | 31.8 ± 0.2
Day 23 | 32.5 ± 0.2 | 32.4 ± 0.2 | 32.7 ± 0.2 | 33.1 ± 0.2 | 32.7 ± 0.3 | 32.7 ± 0.2
Week 14 | 33.4 ± 0.2 | 33.1 ± 0.2 | 33.2 ± 0.2 | 33.3 ± 0.1 | 33.3 ± 0.2 | 33.3 ± 0.2
Platelets (10^3^/μL)
Day 4 | 1,237 ± 34 | 1,282 ± 44 | 1,236 ± 33 | 1,322 ± 41 | 1,290 ± 31 | 1,242 ± 47
Day 23 | 1,027 ± 18 | 1,068 ± 29 | 1,069 ± 18 | 1,074 ± 22 | 998 ± 46 | 1,069 ± 34
Week 14 | 718 ± 22 | 701 ± 14 | 711 ± 17 | 715 ± 26 | 672 ± 23 | 712 ± 11
Leukocytes (10^3^/μL)
Day 4 | 7.19 ± 0.36 | 7.54 ± 0.39 | 6.83 ± 0.47 | 6.84 ± 0.70 | 7.07 ± 0.29 | 7.78 ± 0.41
Day 23 | 8.26 ± 0.92 | 8.09 ± 0.67 | 7.39 ± 0.65 | 7.12 ± 0.66 | 7.47 ± 0.71 | 6.93 ± 0.88
Week 14 | 7.77 ± 0.24 | 7.34 ± 0.15 | 7.45 ± 0.53 | 7.41 ± 0.30 | 7.21 ± 0.40 | 7.82 ± 0.35
Segmented neutrophils (10^3^/μL)
Day 4 | 1.53 ± 0.11 | 1.59 ± 0.09 | 1.53 ± 0.14 | 1.53 ± 0.20 | 1.46 ± 0.10 | 1.70 ± 0.12
Day 23 | 1.52 ± 0.20 | 1.56 ± 0.21 | 1.53 ± 0.18 | 1.29 ± 0.11 | 1.41 ± 0.13 | 1.68 ± 0.25
Week 14 | 1.29 ± 0.10 | 1.35 ± 0.09 | 1.42 ± 0.12 | 1.22 ± 0.08 | 1.27 ± 0.11 | 1.43 ± 0.17
Lymphocytes (10^3^/μL)
Day 4 | 5.26 ± 0.29 | 5.53 ± 0.36 | 4.92 ± 0.33 | 4.98 ± 0.46 | 5.20 ± 0.24 | 5.65 ± 0.29
Day 23 | 6.36 ± 0.70 | 6.19 ± 0.47 | 5.52 ± 0.46 | 5.54 ± 0.57 | 5.76 ± 0.59 | 4.93 ± 0.60
Week 14 | 6.21 ± 0.17 | 5.71 ± 0.17 | 5.76 ± 0.42 | 5.88 ± 0.25 | 5.62 ± 0.36 | 6.09 ± 0.24
Monocytes (10^3^/μL)
Day 4 | 0.26 ± 0.02 | 0.26 ± 0.02 | 0.25 ± 0.03 | 0.22 ± 0.03 | 0.25 ± 0.02 | 0.28 ± 0.02
Day 23 | 0.23 ± 0.04 | 0.21 ± 0.03 | 0.19 ± 0.03 | 0.17 ± 0.02 | 0.16 ± 0.02 | 0.19 ± 0.03
Week 14 | 0.17 ± 0.01 | 0.16 ± 0.01 | 0.18 ± 0.02 | 0.19 ± 0.02 | 0.20 ± 0.03 | 0.18 ± 0.02
Basophils (10^3^/μL)
Day 4 | 0.070 ± 0.016 | 0.082 ± 0.012 | 0.078 ± 0.012 | 0.064 ± 0.015 | 0.077 ± 0.007 | 0.085 ± 0.011
Day 23 | 0.068 ± 0.015 | 0.053 ± 0.005 | 0.049 ± 0.007 | 0.050 ± 0.009 | 0.054 ± 0.011 | 0.045 ± 0.008
Week 14 | 0.026 ± 0.002 | 0.023 ± 0.002 | 0.023 ± 0.003 | 0.024 ± 0.003 | 0.023 ± 0.004 | 0.022 ± 0.004
Eosinophils (10^3^/μL)
Day 4 | 0.07 ± 0.01 | 0.08 ± 0.02 | 0.06 ± 0.01 | 0.04 ± 0.01 | 0.08 ± 0.02 | 0.07 ± 0.02
Day 23 | 0.08 ± 0.01 | 0.08 ± 0.01 | 0.09 ± 0.01 | 0.07 ± 0.01 | 0.08 ± 0.01 | 0.08 ± 0.01
Week 14 | 0.08 ± 0.01 | 0.10 ± 0.01 | 0.07 ± 0.01 | 0.10 ± 0.01 | 0.09 ± 0.01 | 0.09 ± 0.01
Clinical Chemistry
n | 10 | 10 | 10 | 10 | 10 | 10
Urea nitrogen (mg/dL)
Day 4 | 10.5 ± 0.4 | 9.7 ± 0.4 | 10.2 ± 0.4 | 9.6 ± 0.5 | 10.5 ± 0.3 | 9.8 ± 0.6
Day 23 | 12.1 ± 0.3 | 10.9 ± 0.3 | 10.9 ± 0.3 | 11.9 ± 0.5 | 9.9 ± 0.3** | 10.6 ± 0.3**
Week 14 | 15.4 ± 0.5 | 14.9 ± 0.3 | 14.6 ± 0.4 | 14.9 ± 0.5 | 14.7 ± 0.5 | 15.8 ± 0.4
Creatinine (mg/dL)
Day 4 | 0.49 ± 0.01 | 0.47 ± 0.02 | 0.49 ± 0.01 | 0.49 ± 0.01 | 0.48 ± 0.01 | 0.50 ± 0.00
Day 23 | 0.49 ± 0.01 | 0.49 ± 0.01 | 0.49 ± 0.01 | 0.49 ± 0.01 | 0.46 ± 0.02 | 0.49 ± 0.01
Week 14 | 0.69 ± 0.02 | 0.70 ± 0.02 | 0.68 ± 0.02 | 0.68 ± 0.01 | 0.72 ± 0.02 | 0.73 ± 0.04
Glucose (mg/dL)
Day 4 | 132 ± 2 | 135 ± 3 | 135 ± 2 | 138 ± 4 | 137 ± 3 | 133 ± 3
Day 23 | 142 ± 3 | 140 ± 3 | 144 ± 2 | 140 ± 2 | 144 ± 2 | 145 ± 2
Week 14 | 132 ± 3 | 139 ± 4 | 128 ± 4 | 133 ± 4 | 135 ± 7 | 135 ± 4
Total protein (g/dL)
Day 4 | 5.5 ± 0.1 | 5.4 ± 0.0 | 5.5 ± 0.1 | 5.5 ± 0.1 | 5.5 ± 0.1 | 5.6 ± 0.1
Day 23 | 5.9 ± 0.1 | 5.9 ± 0.1 | 5.9 ± 0.0 | 5.9 ± 0.1 | 5.9 ± 0.1 | 5.8 ± 0.1
Week 14 | 7.3 ± 0.1 | 7.2 ± 0.0 | 7.3 ± 0.0 | 7.4 ± 0.0 | 7.3 ± 0.1 | 7.3 ± 0.1
Albumin (g/dL)
Day 4 | 4.0 ± 0.0 | 4.0 ± 0.0 | 4.0 ± 0.0 | 4.0 ± 0.0 | 4.0 ± 0.0 | 4.1 ± 0.0
Day 23 | 4.1 ± 0.0 | 4.1 ± 0.0 | 4.0 ± 0.0 | 4.1 ± 0.0 | 4.1 ± 0.0 | 4.0 ± 0.0
Week 14 | 4.6 ± 0.0 | 4.5 ± 0.0 | 4.6 ± 0.0 | 4.6 ± 0.0 | 4.6 ± 0.0 | 4.5 ± 0.0
Alanine aminotransferase (IU/L)
Day 4 | 66 ± 1 | 64 ± 1 | 68 ± 2 | 65 ± 1 | 65 ± 1 | 66 ± 2
Day 23 | 43 ± 1 | 44 ± 1 | 45 ± 1 | 45 ± 2 | 45 ± 1 | 43 ± 1
Week 14 | 76 ± 6 | 79 ± 4 | 76 ± 3 | 76 ± 3 | 75 ± 2 | 77 ± 4
Alkaline phosphatase (IU/L)
Day 4 | 660 ± 14 | 661 ± 17 | 645 ± 14 | 683 ± 15 | 650 ± 12 | 671 ± 13
Day 23 | 489 ± 10 | 487 ± 8 | 475 ± 11 | 482 ± 8 | 507 ± 12 | 489 ± 9
Week 14 | 250 ± 6 | 232 ± 3 | 231 ± 3 | 230 ± 6 | 234 ± 4 | 232 ± 6
Creatine kinase (IU/L)
Day 4 | 470 ± 57 | 561 ± 101 | 681 ± 99 | 470 ± 60 | 501 ± 81 | 510 ± 94
Day 23 | 334 ± 44 | 342 ± 41 | 356 ± 39 | 375 ± 37 | 248 ± 24 | 365 ± 40
Week 14 | 409 ± 80 | 625 ± 90 | 272 ± 37 | 336 ± 53 | 353 ± 33 | 338 ± 54
Sorbitol dehydrogenase (IU/L)
Day 4 | 13 ± 1 | 12 ± 1 | 13 ± 0 | 13 ± 1 | 12 ± 1 | 12 ± 0
Day 23 | 16 ± 1 | 15 ± 1 | 15 ± 1 | 14 ± 1 | 14 ± 1 | 14 ± 1
Week 14 | 22 ± 1 | 23 ± 2 | 24 ± 1 | 24 ± 1 | 24 ± 1 | 23 ± 1
Bile acids (µmol/L)
Day 4 | 27.8 ± 4.3 | 28.4 ± 4.5 | 27.2 ± 4.4 | 25.4 ± 4.2 | 24.0 ± 3.2 | 32.2 ± 4.7
Day 23 | 17.2 ± 2.9 | 18.2 ± 2.9 | 19.9 ± 2.0 | 15.7 ± 2.0 | 16.2 ± 2.4 | 15.6 ± 1.1
Week 14 | 9.8 ± 2.2 | 7.2 ± 1.3 | 5.2 ± 0.8 | 5.1 ± 0.6 | 7.9 ± 2.1 | 7.8 ± 1.4
Total thyroxine (mmol/L)
Week 14 | 5.89 ± 0.24 | 5.98 ± 0.25 | 5.89 ± 0.15 | 5.76 ± 0.20 | 5.79 ± 0.17 | 5.77 ± 0.16
Female
Hematology
n
Day 4 | 10 | 9 | 10 | 10 | 9 | 10
Day 23 | 9 | 10 | 9 | 10 | 10 | 10
Week 14 | 10 | 9 | 10 | 10 | 8 | 10
Hematocrit (%)
Day 4 | 42.6 ± 0.6 | 45.9 ± 1.2* | 44.4 ± 0.8 | 43.5 ± 0.6 | 43.6 ± 0.5 | 44.3 ± 0.6
Day 23 | 42.4 ± 0.2 | 42.9 ± 0.7 | 43.8 ± 0.5 | 42.9 ± 0.4 | 41.9 ± 0.5 | 42.5 ± 0.5
Week 14 | 45.0 ± 0.5 | 44.8 ± 0.5 | 45.0 ± 0.5 | 44.9 ± 0.3 | 45.1 ± 0.5 | 44.9 ± 0.3
Hemoglobin (g/dL)
Day 4 | 13.7 ± 0.2 | 14.7 ± 0.3 | 14.3 ± 0.3 | 14.0 ± 0.2 | 14.0 ± 0.2 | 14.3 ± 0.2
Day 23 | 14.2 ± 0.1 | 14.3 ± 0.2 | 14.5 ± 0.1 | 14.3 ± 0.1 | 13.9 ± 0.1 | 14.2 ± 0.1
Week 14 | 15.4 ± 0.1 | 15.3 ± 0.1 | 15.3 ± 0.2 | 15.4 ± 0.1 | 15.5 ± 0.2 | 15.4 ± 0.1
Erythrocytes (10^6^/μL)
Day 4 | 7.20 ± 0.09 | 7.77 ± 0.17** | 7.53 ± 0.14 | 7.41 ± 0.07 | 7.45 ± 0.07 | 7.43 ± 0.09
Day 23 | 7.76 ± 0.04 | 7.87 ± 0.11 | 8.00 ± 0.09 | 7.89 ± 0.07 | 7.75 ± 0.09 | 7.75 ± 0.08
Week 14 | 8.66 ± 0.08 | 8.66 ± 0.08 | 8.60 ± 0.10 | 8.62 ± 0.06 | 8.65 ± 0.09 | 8.61 ± 0.06
Reticulocytes (10^3^/μL)
Day 4 | 487 ± 19 | 479 ± 34 | 441 ± 10 | 479 ± 20 | 457 ± 20 | 497 ± 17
Day 23 | 168 ± 4 | 179 ± 4 | 169 ± 8 | 176 ± 11 | 169 ± 8 | 181 ± 7
Week 14 | 184 ± 6 | 178 ± 11 | 191 ± 10 | 189 ± 11 | 185 ± 9 | 179 ± 7
Mean cell volume (fL)
Day 4 | 59.2 ± 0.3 | 59.0 ± 0.3 | 59.0 ± 0.3 | 58.8 ± 0.4 | 58.5 ± 0.4 | 59.7 ± 0.3
Day 23 | 54.6 ± 0.2 | 54.5 ± 0.3 | 54.8 ± 0.1 | 54.4 ± 0.2 | 54.0 ± 0.2 | 54.8 ± 0.1
Week 14 | 52.0 ± 0.3 | 51.7 ± 0.2 | 52.3 ± 0.2 | 52.1 ± 0.1 | 52.1 ± 0.2 | 52.1 ± 0.2
Mean cell hemoglobin (pg)
Day 4 | 19.0 ± 0.1 | 18.9 ± 0.1 | 19.0 ± 0.1 | 18.9 ± 0.2 | 18.8 ± 0.1 | 19.2 ± 0.1
Day 23 | 18.4 ± 0.1 | 18.2 ± 0.1 | 18.1 ± 0.1 | 18.2 ± 0.1 | 18.0 ± 0.1 | 18.3 ± 0.1
Week 14 | 17.8 ± 0.1 | 17.7 ± 0.1 | 17.9 ± 0.1 | 17.9 ± 0.1 | 17.9 ± 0.1 | 17.8 ± 0.1
Mean cell hemoglobin concentration (g/dL)
Day 4 | 32.2 ± 0.1 | 32.0 ± 0.2 | 32.1 ± 0.1 | 32.1 ± 0.1 | 32.1 ± 0.2 | 32.2 ± 0.2
Day 23 | 33.6 ± 0.1 | 33.3 ± 0.1 | 33.1 ± 0.2 | 33.4 ± 0.1 | 33.4 ± 0.2 | 33.4 ± 0.2
Week 14 | 34.3 ± 0.1 | 34.1 ± 0.1 | 34.1 ± 0.1 | 34.4 ± 0.1 | 34.3 ± 0.1 | 34.3 ± 0.1
Platelets (10^3^/μL)
Day 4 | 1,093 ± 23 | 1,031 ± 34 | 1,097 ± 48 | 1,029 ± 30 | 1,143 ± 39 | 1,064 ± 58
Day 23 | 960 ± 41 | 966 ± 26 | 855 ± 55 | 902 ± 50 | 916 ± 29 | 951 ± 45
Week 14 | 735 ± 19 | 717 ± 24 | 741 ± 22 | 739 ± 23 | 708 ± 36 | 707 ± 13
Leukocytes (10^3^/μL)
Day 4 | 6.92 ± 0.49 | 7.27 ± 0.85 | 7.21 ± 0.62 | 7.31 ± 0.44 | 7.01 ± 0.50 | 7.15 ± 0.43
Day 23 | 6.18 ± 0.60 | 6.76 ± 0.66 | 6.48 ± 0.59 | 7.61 ± 0.69 | 5.49 ± 0.64 | 6.79 ± 0.64
Week 14 | 5.45 ± 0.46 | 5.80 ± 0.45 | 5.50 ± 0.55 | 5.84 ± 0.23 | 5.05 ± 0.44 | 6.30 ± 0.32
Segmented neutrophils (10^3^/μL)
Day 4 | 1.20 ± 0.09 | 1.28 ± 0.18 | 1.43 ± 0.16 | 1.24 ± 0.10 | 1.18 ± 0.10 | 1.30 ± 0.10
Day 23 | 1.08 ± 0.12 | 1.38 ± 0.16 | 1.03 ± 0.15 | 1.17 ± 0.16 | 0.99 ± 0.17 | 1.34 ± 0.13
Week 14 | 1.03 ± 0.12 | 1.04 ± 0.09 | 0.99 ± 0.08 | 1.16 ± 0.09 | 1.20 ± 0.19 | 1.24 ± 0.10
Lymphocytes (10^3^/μL)
Day 4 | 5.38 ± 0.41 | 5.63 ± 0.64 | 5.40 ± 0.44 | 5.68 ± 0.35 | 5.47 ± 0.39 | 5.46 ± 0.37
Day 23 | 4.82 ± 0.45 | 5.07 ± 0.50 | 5.21 ± 0.46 | 6.15 ± 0.57 | 4.27 ± 0.44 | 5.15 ± 0.53
Week 14 | 4.15 ± 0.35 | 4.49 ± 0.37 | 4.28 ± 0.45 | 4.41 ± 0.16 | 3.60 ± 0.25 | 4.74 ± 0.25
Monocytes (10^3^/μL)
Day 4 | 0.20 ± 0.02 | 0.22 ± 0.03 | 0.23 ± 0.02 | 0.24 ± 0.02 | 0.21 ± 0.02 | 0.25 ± 0.03
Day 23 | 0.15 ± 0.03 | 0.18 ± 0.03 | 0.11 ± 0.02 | 0.15 ± 0.03 | 0.12 ± 0.03 | 0.18 ± 0.02
Week 14 | 0.18 ± 0.03 | 0.17 ± 0.03 | 0.14 ± 0.02 | 0.17 ± 0.01 | 0.15 ± 0.02 | 0.18 ± 0.02
Basophils (10^3^/μL)
Day 4 | 0.004 ± 0.006 | 0.052 ± 0.012 | 0.061 ± 0.013 | 0.055 ± 0.010 | 0.057 ± 0.012 | 0.058 ± 0.007
Day 23 | 0.028 ± 0.006 | 0.032 ± 0.004 | 0.021 ± 0.007 | 0.038 ± 0.009 | 0.024 ± 0.005 | 0.039 ± 0.006
Week 14 | 0.023 ± 0.004 | 0.028 ± 0.006 | 0.024 ± 0.005 | 0.029 ± 0.003 | 0.020 ± 0.004 | 0.035 ± 0.005
Eosinophils (10^3^/μL)
Day 4 | 0.09 ± 0.01 | 0.09 ± 0.02 | 0.09 ± 0.01 | 0.10 ± 0.02 | 0.10 ± 0.02 | 0.08 ± 0.00
Day 23 | 0.10 ± 0.01 | 0.10 ± 0.01 | 0.10 ± 0.02 | 0.11 ± 0.01 | 0.08 ± 0.02 | 0.09 ± 0.01
Week 14 | 0.07 ± 0.01 | 0.07 ± 0.01 | 0.07 ± 0.01 | 0.07 ± 0.01 | 0.08 ± 0.02 | 0.10 ± 0.01
Clinical Chemistry
n | 10 | 10 | 10 | 10 | 10 | 10
Urea nitrogen (mg/dL)
Day 4 | 9.8 ± 0.6 | 9.7 ± 0.3 | 11.0 ± 0.6 | 10.4 ± 0.4 | 10.7 ± 0.4 | 9.8 ± 0.4
Day 23 | 12.0 ± 0.4 | 12.4 ± 0.4 | 11.4 ± 0.3 | 12.0 ± 0.4 | 12.0 ± 0.4 | 11.3 ± 0.4
Week 14 | 15.9 ± 0.4 | 15.1 ± 0.4 | 14.9 ± 0.6 | 14.5 ± 0.5 | 15.5 ± 0.7 | 14.7 ± 0.4
Creatinine (mg/dL)
Day 4 | 0.37 ± 0.02 | 0.40 ± 0.00 | 0.39 ± 0.01 | 0.38 ± 0.01 | 0.40 ± 0.00 | 0.39 ± 0.01
Day 23 | 0.49 ± 0.01 | 0.50 ± 0.00 | 0.50 ± 0.01 | 0.46 ± 0.02 | 0.48 ± 0.01 | 0.49 ± 0.01
Week 14 | 0.59 ± 0.01 | 0.60 ± 0.00 | 0.62 ± 0.01 | 0.59 ± 0.01 | 0.59 ± 0.02 | 0.59 ± 0.01
Glucose (mg/dL)
Day 4 | 140 ± 4 | 133 ± 3 | 137 ± 4 | 142 ± 3 | 141 ± 2 | 135 ± 3
Day 23 | 134 ± 2 | 132 ± 2 | 131 ± 2 | 133 ± 3 | 136 ± 2 | 135 ± 2
Week 14 | 126 ± 3 | 126 ± 4 | 129 ± 4 | 125 ± 2 | 133 ± 4 | 128 ± 4
Total protein (g/dL)
Day 4 | 5.6 ± 0.1 | 5.6 ± 0.0 | 5.7 ± 0.1 | 5.6 ± 0.1 | 5.5 ± 0.0 | 5.6 ± 0.1
Day 23 | 5.9 ± 0.1 | 6.0 ± 0.1 | 6.0 ± 0.1 | 6.0 ± 0.1 | 5.8 ± 0.1 | 6.0 ± 0.1
Week 14 | 7.3 ± 0.1 | 7.4 ± 0.1 | 7.3 ± 0.1 | 7.4 ± 0.1 | 7.4 ± 0.1 | 7.2 ± 0.1
Albumin (g/dL)
Day 4 | 4.1 ± 0.1 | 4.1 ± 0.0 | 4.2 ± 0.1 | 4.1 ± 0.1 | 4.1 ± 0.0 | 4.1 ± 0.1
Day 23 | 4.3 ± 0.0 | 4.4 ± 0.1 | 4.3 ± 0.1 | 4.4 ± 0.0 | 4.2 ± 0.1 | 4.3 ± 0.1
Week 14 | 5.0 ± 0.1 | 4.9 ± 0.1 | 4.9 ± 0.1 | 5.0 ± 0.1 | 5.0 ± 0.1 | 4.8 ± 0.1
Alanine aminotransferase (IU/L)
Day 4 | 56 ± 1 | 57 ± 3 | 54 ± 2 | 58 ± 2 | 54 ± 2 | 59 ± 2
Day 23 | 33 ± 1 | 35 ± 1 | 33 ± 1 | 33 ± 1 | 33 ± 1 | 35 ± 1
Week 14 | 60 ± 4 | 74 ± 13 | 62 ± 5 | 57 ± 3 | 57 ± 3 | 52 ± 3
Alkaline phosphatase (IU/L)
Day 4 | 587 ± 12 | 568 ± 26 | 577 ± 8 | 596 ± 12 | 562 ± 18 | 609 ± 17
Day 23 | 353 ± 5 | 349 ± 8 | 357 ± 6 | 366 ± 6 | 350 ± 8 | 350 ± 9
Week 14 | 226 ± 5 | 223 ± 9 | 225 ± 9 | 229 ± 5 | 221 ± 5 | 222 ± 6
Creatine kinase (IU/L)
Day 4 | 489 ± 79 | 607 ± 116 | 553 ± 64 | 488 ± 53 | 579 ± 128 | 441 ± 72
Day 23 | 355 ± 48 | 286 ± 25 | 337 ± 28 | 332 ± 41 | 355 ± 42 | 362 ± 37
Week 14 | 247 ± 36 | 287 ± 57 | 311 ± 57 | 293 ± 46^b^ | 315 ± 63 | 254 ± 35
Sorbitol dehydrogenase (IU/L)
Day 4 | 13 ± 0 | 12 ± 1 | 13 ± 1 | 13 ± 1 | 12 ± 1 | 13 ± 0
Day 23 | 14 ± 1 | 15 ± 1 | 15 ± 1 | 15 ± 0 | 14 ± 1 | 15 ± 1
Week 14 | 16 ± 1 | 19 ± 3 | 18 ± 1 | 16 ± 1 | 16 ± 1 | 15 ± 1
Bile acids (µmol/L)
Day 4 | 25.0 ± 3.4 | 18.6 ± 2.3 | 19.6 ± 3.3 | 22.9 ± 3.7 | 24.4 ± 3.6 | 23.4 ± 2.2
Day 23 | 17.4 ± 2.8 | 11.7 ± 2.2 | 11.6 ± 1.7 | 11.2 ± 2.1 | 12.4 ± 2.0 | 11.4 ± 1.5
Week 14 | 12.8 ± 1.9 | 15.2 ± 2.4 | 14.4 ± 2.4 | 9.9 ± 1.6 | 13.3 ± 2.3 | 14.7 ± 2.3
Total thyroxine (mmol/L)
Week 14 | 3.01 ± 0.26 | 3.17 ± 0.20 | 3.79 ± 0.29 | 3.53 ± 0.34 | 3.18 ± 0.38 | 3.59 ± 0.33

* Significantly different (P ≤ 0.05) from the vehicle control group by Dunn’s test.

** P ≤ 0.01.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.

^b^ n = 9.

Table B-2 Hematology Data for Mice in the Three-month Dermal Study of 5-Amino-o-cresol^a^

| Vehicle Control | 8 mg/kg | 16 mg/kg | 32 mg/kg | 64 mg/kg | 128 mg/kg
Male
n | 10 | 10 | 10 | 9 | 10 | 9
Hematocrit (%) | 51.3 ± 0.8 | 50.9 ± 0.3 | 50.7 ± 0.7 | 50.8 ± 0.7 | 50.6 ± 0.4 | 50.5 ± 0.4
Hemoglobin (g/dL) | 15.9 ± 0.3 | 15.7 ± 0.1 | 15.7 ± 0.2 | 15.7 ± 0.2 | 15.7 ± 0.2 | 15.6 ± 0.1
Erythrocytes (10^6^/µL) | 10.36 ± 0.15 | 10.35 ± 0.06 | 10.37 ± 0.14 | 10.25 ± 0.11 | 10.30 ± 0.07 | 10.28 ± 0.08
Reticulocytes (10^3^/µL) | 274 ± 9 | 287 ± 8 | 283 ± 6 | 280 ± 8 | 268 ± 7 | 277 ± 13
Mean cell volume (fL) | 49.5 ± 0.1 | 49.2 ± 0.2 | 48.9 ± 0.1 | 49.5 ± 0.3 | 49.2 ± 0.2 | 49.2 ± 0.2
Mean cell hemoglobin (pg) | 15.4 ± 0.1 | 15.2 ± 0.1 | 15.1 ± 0.1 | 15.3 ± 0.1 | 15.2 ± 0.1 | 15.2 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 31.1 ± 0.1 | 30.9 ± 0.1 | 31.0 ± 0.1 | 30.9 ± 0.1 | 30.9 ± 0.1 | 30.9 ± 0.2
Platelets (10^3^/µL) | 999 ± 34 | 1,027 ± 29 | 966 ± 42 | 1,003 ± 17 | 995 ± 33 | 1,071 ± 30
Leukocytes (10^3^/µL) | 4.81 ± 0.52 | 5.09 ± 0.43 | 4.70 ± 0.35 | 4.61 ± 0.21 | 4.70 ± 0.31 | 4.90 ± 0.37
Segmented neutrophils (10^3^/µL) | 0.64 ± 0.05 | 0.69 ± 0.06 | 0.65 ± 0.05 | 0.64 ± 0.05 | 0.69 ± 0.07 | 0.72 ± 0.07
Lymphocytes (10^3^/µL) | 3.89 ± 0.44 | 4.13 ± 0.38 | 3.76 ± 0.28 | 3.69 ± 0.20 | 3.76 ± 0.25 | 3.89 ± 0.31
Monocytes (10^3^/µL) | 0.19 ± 0.03 | 0.19 ± 0.02 | 0.21 ± 0.03 | 0.20 ± 0.02 | 0.17 ± 0.03 | 0.21 ± 0.02
Basophils (10^3^/µL) | 0.009 ± 0.002 | 0.010 ± 0.002 | 0.009 ± 0.001 | 0.006 ± 0.002 | 0.005 ± 0.002 | 0.011 ± 0.001
Eosinophils (10^3^/µL) | 0.08 ± 0.02 | 0.08 ± 0.01 | 0.08 ± 0.01 | 0.06 ± 0.01 | 0.07 ± 0.02 | 0.07 ± 0.01
Female
n | 10 | 10 | 10 | 7 | 10 | 10
Hematocrit (%) | 51.2 ± 0.7 | 51.7 ± 0.4 | 52.7 ± 0.9 | 50.7 ± 0.4 | 51.3 ± 0.6 | 51.2 ± 0.4
Hemoglobin (g/dL) | 16.2 ± 0.3 | 16.3 ± 0.2 | 16.6 ± 0.3 | 16.0 ± 0.1 | 16.2 ± 0.2 | 16.1 ± 0.2
Erythrocytes (10^6^/µL) | 10.33 ± 0.15 | 10.39 ± 0.10 | 10.54 ± 0.17 | 10.14 ± 0.09 | 10.31 ± 0.11 | 10.31 ± 0.09
Reticulocytes (10^3^/µL) | 273 ± 14 | 283 ± 20 | 293 ± 12 | 254 ± 9 | 279 ± 15 | 274 ± 10
Mean cell volume (fL) | 49.6 ± 0.1 | 49.7 ± 0.2 | 50.0 ± 0.2 | 50.0 ± 0.1 | 49.7 ± 0.1 | 49.7 ± 0.2
Mean cell hemoglobin (pg) | 15.7 ± 0.1 | 15.7 ± 0.1 | 15.8 ± 0.1 | 15.8 ± 0.1 | 15.7 ± 0.1 | 15.6 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 31.6 ± 0.1 | 31.5 ± 0.2 | 31.5 ± 0.1 | 31.6 ± 0.1 | 31.5 ± 0.2 | 31.4 ± 0.1
Platelets (10^3^/µL) | 907 ± 37 | 911 ± 39 | 859 ± 30 | 949 ± 33 | 905 ± 67 | 848 ± 48
Leukocytes (10^3^/µL) | 5.02 ± 0.27 | 5.43 ± 0.41 | 4.76 ± 0.32 | 4.97 ± 0.35 | 4.91 ± 0.39 | 5.04 ± 0.33
Segmented neutrophils (10^3^/µL) | 0.77 ± 0.05 | 0.70 ± 0.06 | 0.79 ± 0.10 | 0.65 ± 0.09 | 0.72 ± 0.10 | 0.77 ± 0.08
Lymphocytes (10^3^/µL) | 4.01 ± 0.27 | 4.50 ± 0.34 | 3.77 ± 0.23 | 4.07 ± 0.26 | 3.93 ± 0.28 | 4.07 ± 0.30
Monocytes (10^3^/µL) | 0.12 ± 0.01 | 0.14 ± 0.02 | 0.13 ± 0.02 | 0.15 ± 0.04 | 0.14 ± 0.02 | 0.11 ± 0.02
Basophils (10^3^/µL) | 0.015 ± 0.002 | 0.015 ± 0.003 | 0.010 ± 0.002 | 0.011 ± 0.003 | 0.011 ± 0.003 | 0.011 ± 0.003
Eosinophils (10^3^/µL) | 0.10 ± 0.01 | 0.08 ± 0.01 | 0.06 ± 0.01 | 0.09 ± 0.02 | 0.11 ± 0.02 | 0.08 ± 0.01

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.