# Appendix A Summary of Lesions in Rats and Mice

Table A-1 Summary of the Incidence of Nonneoplastic Lesions in Male Rats in the Three-month Dermal Study of 5-Amino-o-cresol^a^

| Vehicle Control | 2 mg/kg | 4 mg/kg | 8 mg/kg | 16 mg/kg | 32 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Survivors
Terminal kill | 10 | 10 | 10 | 10 | 10 | 10
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Esophagus | (10) | (0) | (0) | (0) | (0) | (10)
Intestine large, cecum | (10) | (0) | (0) | (0) | (0) | (10)
Intestine large, colon | (10) | (0) | (0) | (0) | (0) | (10)
Intestine large, rectum | (10) | (0) | (0) | (0) | (0) | (10)
Parasite metazoan | – | – | – | – | – | 2 (20%)
Intestine small, duodenum | (10) | (0) | (0) | (0) | (0) | (10)
Intestine small, ileum | (10) | (0) | (0) | (0) | (0) | (10)
Intestine small, jejunum | (10) | (0) | (0) | (0) | (0) | (10)
Liver | (10) | (10) | (10) | (10) | (10) | (10)
Hepatodiaphragmatic nodule | – | – | – | 1 (10%) | – | –
Inflammation, chronic active | 9 (90%) | – | – | 1 (10%) | – | 9 (90%)
Pancreas | (10) | (0) | (0) | (0) | (0) | (10)
Inflammation, chronic active | 1 (10%) | – | – | – | – | –
Acinus, atrophy | – | – | – | – | – | 2 (20%)
Salivary glands | (10) | (0) | (0) | (0) | (0) | (10)
Stomach, forestomach | (10) | (0) | (0) | (0) | (0) | (10)
Stomach, glandular | (10) | (0) | (0) | (0) | (0) | (10)
Cardiovascular System
Blood vessel | (10) | (0) | (0) | (0) | (0) | (10)
Heart | (10) | (0) | (0) | (0) | (0) | (10)
Cardiomyopathy | 10 (100%) | – | – | – | – | 10 (100%)
Endocrine System
Adrenal cortex | (10) | (0) | (0) | (0) | (0) | (10)
Adrenal medulla | (10) | (0) | (0) | (0) | (0) | (10)
Infiltration cellular, mononuclear cell | 1 (10%) | – | – | – | – | 2 (20%)
Islets, pancreatic | (10) | (0) | (0) | (0) | (0) | (10)
Parathyroid gland | (9) | (0) | (0) | (0) | (0) | (9)
Pituitary gland | (10) | (0) | (0) | (0) | (0) | (10)
Cyst | 1 (10%) | – | – | – | – | –
Thyroid gland | (10) | (10) | (10) | (10) | (10) | (10)
Infiltration cellular, mononuclear cell | – | – | – | – | – | 1 (10%)
General Body System
None | – | – | – | – | – | –
Genital System
Epididymis | (10) | (0) | (0) | (0) | (0) | (10)
Infiltration cellular, mononuclear cell | 1 (10%) | – | – | – | – | –
Inflammation, chronic active | – | – | – | – | – | 2 (20%)
Preputial gland | (10) | (0) | (0) | (0) | (0) | (10)
Prostate | (10) | (0) | (0) | (0) | (0) | (10)
Seminal vesicle | (10) | (0) | (0) | (0) | (0) | (10)
Testes | (10) | (0) | (0) | (0) | (0) | (10)
Hematopoietic System
Bone marrow | (10) | (0) | (0) | (0) | (0) | (10)
Lymph node, mandibular | (10) | (0) | (0) | (0) | (0) | (10)
Lymph node, mesenteric | (10) | (0) | (0) | (0) | (0) | (10)
Inflammation, histiocytic | – | – | – | – | – | 1 (10%)
Spleen | (10) | (0) | (0) | (0) | (0) | (10)
Thymus | (10) | (0) | (0) | (0) | (0) | (10)
Integumentary System
Mammary gland | (10) | (0) | (0) | (0) | (0) | (10)
Skin | (10) | (0) | (0) | (0) | (0) | (10)
Musculoskeletal System
Bone | (10) | (0) | (0) | (0) | (0) | (10)
Nervous System
Brain | (10) | (0) | (0) | (0) | (0) | (10)
Respiratory System
Lung | (10) | (10) | (10) | (10) | (10) | (10)
Infiltration cellular, histiocyte | 2 (20%) | – | – | – | – | 4 (40%)
Inflammation, chronic active | 3 (30%) | 5 (50%) | 7 (70%) | 8 (80%) | 6 (60%) | 5 (50%)
Metaplasia, osseous | 2 (20%) | – | – | – | – | 1 (10%)
Nose | (10) | (0) | (0) | (0) | (0) | (10)
Trachea | (10) | (0) | (0) | (0) | (0) | (10)
Infiltration cellular, mononuclear cell | 5 (50%) | – | – | – | – | 3 (30%)
Special Senses System
Eye | (10) | (0) | (0) | (0) | (0) | (10)
Harderian gland | (10) | (0) | (0) | (0) | (0) | (10)
Infiltration cellular, mononuclear cell | – | – | – | – | – | 1 (10%)
Inflammation, chronic active | 1 (10%) | – | – | – | – | 1 (10%)
Urinary System
Kidney | (10) | (0) | (0) | (0) | (0) | (10)
Infiltration cellular, mononuclear cell | 1 (10%) | – | – | – | – | 1 (10%)
Mineralization | 6 (60%) | – | – | – | – | 6 (60%)
Nephropathy | 10 (100%) | – | – | – | – | 10 (100%)
Urinary bladder | (10) | (0) | (0) | (0) | (0) | (10)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.

Table A-2 Summary of the Incidence of Nonneoplastic Lesions in Female Rats in the Three-month Dermal Study of 5-Amino-o-cresol^a^

| Vehicle Control | 2 mg/kg | 4 mg/kg | 8 mg/kg | 16 mg/kg | 32 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Survivors
Terminal kill | 10 | 10 | 10 | 10 | 10 | 10
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Esophagus | (10) | (0) | (0) | (0) | (0) | (10)
Intestine large, cecum | (10) | (0) | (0) | (0) | (0) | (10)
Intestine large, colon | (10) | (0) | (0) | (0) | (0) | (10)
Intestine large, rectum | (10) | (0) | (0) | (0) | (0) | (10)
Parasite metazoan | 1 (10%) | – | – | – | – | –
Intestine small, duodenum | (10) | (0) | (0) | (0) | (0) | (10)
Intestine small, ileum | (10) | (0) | (0) | (0) | (0) | (10)
Intestine small, jejunum | (10) | (0) | (0) | (0) | (0) | (10)
Liver | (10) | (10) | (10) | (10) | (10) | (10)
Hematopoietic cell proliferation | – | – | – | 1 (10%) | – | –
Hepatodiaphragmatic nodule | 2 (20%) | 3 (30%) | 2 (20%) | 3 (30%) | 2 (20%) | 1 (10%)
Inflammation, chronic active | 10 (100%) | 1 (10%) | 2 (20%) | 2 (20%) | 2 (20%) | 10 (100%)
Pancreas | (10) | (0) | (0) | (0) | (0) | (10)
Acinus, atrophy | 2 (20%) | – | – | – | – | 1 (10%)
Salivary glands | (10) | (0) | (0) | (0) | (0) | (10)
Infiltration cellular, mononuclear cell | – | – | – | – | – | 1 (10%)
Stomach, forestomach | (10) | (0) | (0) | (0) | (0) | (10)
Stomach, glandular | (10) | (0) | (0) | (0) | (0) | (10)
Cardiovascular System
Blood vessel | (10) | (0) | (0) | (0) | (0) | (10)
Heart | (10) | (0) | (0) | (0) | (0) | (10)
Cardiomyopathy | 10 (100%) | – | – | – | – | 9 (90%)
Endocrine System
Adrenal cortex | (10) | (0) | (0) | (0) | (0) | (10)
Adrenal medulla | (10) | (0) | (0) | (0) | (0) | (10)
Islets, pancreatic | (10) | (0) | (0) | (0) | (0) | (10)
Parathyroid gland | (7) | (0) | (0) | (0) | (0) | (8)
Pituitary gland | (10) | (0) | (0) | (0) | (0) | (10)
Thyroid gland | (10) | (10) | (10) | (10) | (10) | (10)
Infiltration cellular, mononuclear cell | – | – | – | – | – | 1 (10%)
General Body System
None | – | – | – | – | – | –
Genital System
Clitoral gland | (10) | (0) | (0) | (0) | (0) | (10)
Ovary | (10) | (0) | (0) | (1) | (0) | (10)
Left, cyst | – | – | – | 1 (100%) | – | –
Left, inflammation | – | – | – | 1 (100%) | – | –
Uterus | (10) | (0) | (0) | (0) | (0) | (10)
Hematopoietic System
Bone marrow | (10) | (0) | (0) | (0) | (0) | (10)
Infiltration, cellular, histiocyte | – | – | – | – | – | 1 (10%)
Lymph node, mandibular | (10) | (0) | (0) | (0) | (0) | (10)
Lymph node, mesenteric | (10) | (0) | (0) | (0) | (0) | (10)
Inflammation, histiocytic | – | – | – | – | – | 5 (50%)
Spleen | (10) | (0) | (0) | (0) | (0) | (10)
Thymus | (10) | (0) | (0) | (0) | (0) | (10)
Integumentary System
Mammary gland | (10) | (0) | (0) | (0) | (0) | (10)
Skin | (10) | (0) | (0) | (0) | (0) | (10)
Musculoskeletal System
Bone | (10) | (0) | (0) | (0) | (0) | (10)
Nervous System
Brain | (10) | (0) | (0) | (0) | (0) | (10)
Respiratory System
Lung | (10) | (10) | (10) | (10) | (10) | (10)
Infiltration cellular, histiocyte | – | – | – | – | – | 1 (10%)
Inflammation, chronic active | 2 (20%) | 2 (20%) | 6 (60%) | 3 (30%) | 5 (50%) | 6 (60%)
Nose | (10) | (0) | (0) | (0) | (0) | (10)
Inflammation, chronic active | – | – | – | – | – | 2 (20%)
Trachea | (10) | (0) | (0) | (0) | (0) | (10)
Infiltration cellular, mononuclear cell | 3 (30%) | – | – | – | – | 1 (10%)
Special Senses System
Eye | (10) | (0) | (0) | (0) | (0) | (10)
Harderian gland | (10) | (0) | (0) | (0) | (0) | (10)
Infiltration cellular, mononuclear cell | – | – | – | – | – | 2 (20%)
Inflammation, chronic active | 1 (10%) | – | – | – | – | 3 (30%)
Urinary System
Kidney | (10) | (0) | (0) | (0) | (0) | (10)
Infiltration cellular, lipocyte | 1 (10%) | – | – | – | – | –
Infiltration cellular, mononuclear cell | 1 (10%) | – | – | – | – | –
Mineralization | 7 (70%) | – | – | – | – | 7 (70%)
Nephropathy | 3 (30%) | – | – | – | – | –
Urinary bladder | (10) | (0) | (0) | (0) | (0) | (10)
Infiltration cellular, mononuclear cell | 1 (10%) | – | – | – | – | 1 (10%)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.

Table A-3 Summary of the Incidence of Nonneoplastic Lesions in Male Mice in the Three-month Dermal Study of 5-Amino-o-cresol^a^

| Vehicle Control | 8 mg/kg | 16 mg/kg | 32 mg/kg | 64 mg/kg | 128 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Survivors
Terminal kill | 10 | 10 | 10 | 10 | 10 | 10
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | (0) | (0) | (0) | (0) | (10)
Inflammation | 7 (70%) | – | – | – | – | 10 (100%)
Stomach, glandular | (10) | (0) | (0) | (0) | (0) | (10)
Muscularis, hypertrophy | 1 (10%) | – | – | – | – | –
Cardiovascular System
None
Endocrine System
Adrenal cortex | (10) | (0) | (0) | (0) | (0) | (10)
Fibrosis | – | – | – | – | – | 1 (10%)
Hypertrophy | 1 (10%) | – | – | – | – | –
Subcapsular, hyperplasia | 2 (20%) | – | – | – | – | –
General Body System
None | – | – | – | – | – | –
Genital System
Preputial gland | (10) | (0) | (0) | (0) | (0) | (10)
Inflammation | – | – | – | – | – | 1 (10%)
Hematopoietic System
None | – | – | – | – | – | –
Integumentary System
None | – | – | – | – | – | –
Musculoskeletal System
None | – | – | – | – | – | –
Nervous System
None | – | – | – | – | – | –
Respiratory System
Lung | (10) | (10) | (10) | (10) | (10) | (10)
Bronchiole, hyperplasia | – | 2 (20%) | 2 (20%) | – | – | –
Special Senses System
None | – | – | – | – | – | –
Urinary System
Kidney | (10) | (10) | (10) | (10) | (10) | (10)
Inflammation | 1 (10%) | – | – | – | – | –
Mineralization | 1 (10%) | – | – | – | – | 1 (10%)
Nephropathy | 1 (10%) | – | – | – | – | 3 (30%)
Renal tubule, nephropathy | – | – | – | – | – | 1 (10%)
Renal tubule, regeneration | – | – | – | – | – | 1 (10%)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.

Table A-4 Summary of the Incidence of Neoplasms and Nonneoplastic Lesions in Female Mice in the Three-month Dermal Study of 5-Amino-o-cresol^a^

| Vehicle Control | 8 mg/kg | 16 mg/kg | 32 mg/kg | 64 mg/kg | 128 mg/kg
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Early deaths
Natural death | – | – | – | 1 | – | –
Survivors
Terminal kill | 10 | 10 | 10 | 9 | 10 | 10
Animals examined microscopically | 10 | 10 | 10 | 10 | 10 | 10
Alimentary System
Liver | (10) | (0) | (0) | (1) | (0) | (10)
Inflammation | 10 (100%) | – | – | – | – | 8 (80%)
Stomach, glandular | (10) | (0) | (0) | (1) | (0) | (10)
Cyst | – | – | – | – | – | 1 (10%)
Cardiovascular System
Heart | (10) | (0) | (0) | (1) | (0) | (10)
Cardiomyopathy | 2 (20%) | – | – | – | – | –
Epicardium, hyperplasia, focal | – | – | – | – | – | 1 (10%)
Endocrine System
Adrenal cortex | (10) | (0) | (0) | (1) | (0) | (10)
Subcapsular, hyperplasia | 10 (100%) | – | – | 1 (100%) | – | 9 (90%)
General Body System
None | – | – | – | – | – | –
Genital System
Ovary | (10) | (0) | (0) | (1) | (0) | (10)
Left, teratoma benign | – | – | – | 1 (100%) | – | –
Hematopoietic System
None | – | – | – | – | – | –
Integumentary System
None | – | – | – | – | – | –
Musculoskeletal System
None | – | – | – | – | – | –
Nervous System
None | – | – | – | – | – | –
Respiratory System
Lung | (10) | (10) | (10) | (10) | (10) | (10)
Inflammation, chronic | – | – | – | – | – | 1 (10%)
Inflammation, chronic active | – | – | – | 1 (10%) | – | –
Alveolar epithelium, hyperplasia | – | – | – | – | – | 1 (10%)
Alveolar epithelium, bronchiole, metaplasia | – | – | – | – | – | 1 (10%)
Special Senses System
None | – | – | – | – | – | –
Urinary System
Kidney | (10) | (10) | (10) | (10) | (10) | (10)
Inflammation | 1 (10%) | – | – | – | – | –
Mineralization | 2 (20%) | – | – | – | – | 2 (20%)
Nephropathy | 2 (20%) | – | – | – | – | 2 (20%)

^a^ Number of animals examined microscopically at the site and the number of animals with lesion.