# Peer Review

The draft NTP Technical Report on the Toxicity Studies of p-Toluenesulfonamide (CASRN 70-55-3) Administered in Feed to F344/N Rats, F344/NTac Rats, and B6C3F1/N Mice was evaluated by the reviewers listed below. These reviewers served as independent scientists, not as representatives of any institution, company, or governmental agency. In this capacity, reviewers determined if the design and conditions of these NTP studies were appropriate and ensured that this Toxicity Study Report presents the experimental results and conclusions fully and clearly.

## Peer Reviewers

- Susan P. Felter, Ph.D.
  Procter and Gamble
  Cincinnati, Ohio, USA
- Michele A. La Merrill, Ph.D., MPH
  University of California, Davis
  Davis, California, USA
- Melissa G. Rhodes, Ph.D.
  Roivant Sciences, Inc.
  Durham, North Carolina, USA