# References

1 OECD High Production Volume Chemicals Programme/Screening Information Data Set (OECD/SIDS). p-Toluenesulfonamide CAS No. 70-55-3. IRPTC Data Profile: UNEP Publications; 1994. http://www.inchem.org/documents/sids/sids/70553.pdf. [Accessed October 17, 2013]
2 National Institutes for Occupational Safety and Health (NIOSH). Hazardous Substances Data Bank (HSDB) entry for: p-Toluenesulfonamide. 2012. https://toxnet.nlm.nih.gov/cgi-bin/sis/htmlgen?HSDB [Accessed October 17, 2013]
3 Meffe R Kohfahl C Holzbecher E Massmann G Richter D Dünnbier U Pekdeger A Modelling the removal of p-TSA (para-toluenesulfonamide) during rapid sand filtration used for drinking water treatment. Water Res. 2010; 44(1):205–213. http://dx.doi.org/10.1016/j.watres.2009.08.046 19766287
4 Meinertz JR Stehly GR Gingerich WH Greseth SL Performance of a proposed determinative method for p-TSA in rainbow trout fillet tissue and bridging the proposed method with a method for total chloramine-T residues in rainbow trout fillet tissue. J AOAC Int. 2001; 84(5):1332–1336. 11601449
5 Richter D Dünnbier U Massmann G Pekdeger A Quantitative determination of three sulfonamides in environmental water samples using liquid chromatography coupled to electrospray tandem mass spectrometry. J Chromatogr A. 2007; 1157(1-2):115–121. http://dx.doi.org/10.1016/j.chroma.2007.04.042 17477930
6 Ball LM Williams RT Renwick AG The fate of saccharin impurities: The excretion and metabolism of [^14^C]toluene-4-sulphonamide and 4-sulphamoyl[^14^C]benzoic acid in the rat. Xenobiotica. 1978; 8(3):183–190. http://dx.doi.org/10.3109/00498257809060398 654313
7 He J Ying W Yang H Xu X Shao W Guan Y Jiang M Wu Y Zhong B Wang D Gemcitabine plus cisplatin chemotherapy with concurrent para-toluenesulfonamide local injection therapy for peripherally advanced nonsmall cell lung cancer larger than 3 cm in the greatest dimension. Anticancer Drugs. 2009; 20(9):838–844. http://dx.doi.org/10.1097/CAD.0b013e32832fe48f 19668080
8 Buening J Chloramine T pivotal study conducted at Genoa NFH. Fish Lines. 2010; 8:19.
9 United States Fish and Wildlife Service (USFWS). Study protocol for an aquaculture Investigational New Animal Drug (INAD) exemption for chloramine-T. Bozeman, MT: Aquatic Animal Drug Approval Partnership Program; 2007. INAD #9321.
10 United States Fish and Wildlife Service (USFWS). Fact sheet: Chloramine-T INAD 9321, 7 May 2008. Bozeman (MT): Aquatic Animal Drug Approval Partnership Program; 2008.
11 Bullock G, Herman R, Waggy C. Hatchery efficacy trials with chloramine‐T for control of bacterial gill disease. J Aquat Anim Health. 1991; 3(1):48-50. http://dx.doi.org/10.1577/1548-8667(1991)003<0048:HETWCT>2.3.CO;2
12 Gaikowski MP Larson WJ Gingerich WH Survival of cool and warm freshwater fish following chloramine-T exposure. Aquaculture. 2008; 275(1-4):20–25.http://dx.doi.org/10.1016/j.aquaculture.2007.12.017
13 European Medicines Evaluation Agency (EMEA) Tosylchloramide Sodium (extension to horses): Summary Report (3). London, UK: European Medicines Agency, Veterinary Medicines and Inspections, Committee for Medicinal Products for Veterinary Use; 2005.
14 Beljaars PR van Dijk R Brands A Determination of p-toluenesulfonamide in ice cream by combination of continuous flow and liquid chromatography: summary of collaborative study. J AOAC Int. 1994;77(3):672–674. 8012218
15 Drugs-about.com. Pharmaceutical and healthcare online databases. Available forms, composition and doses of chlorazene whirlpool antiseptic. 2011. https://drugs-about.com/drugs-c/chlorazene-whirlpool-antiseptic.html [Accessed October 22, 2013]
16 Russell A Yarnych V Koulikovskii A Guidelines on disinfection in animal husbandry for prevention and control of zoonotic diseases. Geneva, Switzerland: World Health Organization, Veterinary Public Health Unit; 1984.
17 Cardeal ZL Gallet JP Astier A Pradeau D Cyanide assay: statistical comparison of a new gas chromatographic calibration method versus the classical spectrophotometric method. J Anal Toxicol. 1995; 19(1):31–34. http://dx.doi.org/10.1093/jat/19.1.31 7723299
18 United States Environmental Protection Agency (USEPA). Inventory Update Reporting (IUR): Non-confidential 2006 IUR records by chemical, including manufacturing, processing and use information. United States Environmental Protection Agency (USEPA); 2011. https://www.epa.gov/oppt/iur/tools/data/index.html [Accessed: October 22, 2013]
19 National Institute for Occupational Safety and Health (NIOSH). National Occupational Exposure Survey (1981-1983) [unpublished provisional data as of July 1, 1990]. Cincinnati, OH. 1990.
20 United States Environmental Protection Agency (USEPA). Biodegradation: Test substance (70-55-3) Benzenesulfonamide, 4-methyl-. High Production Volume Information System (HPVIS); 2011. https://iaspub.epa.gov/oppthpv/Public_Search.PublicTabs?SECTION=1&epcount=1&v_rs_list=25314018 [Accessed October 22, 2013]
21 Minegishi K-I Asahina M Yamaha T The metabolism of saccharin and the related compounds in rats and guinea pigs. Chem Pharm Bull (Tokyo). 1972; 20(7):1351–1356. http://dx.doi.org/10.1248/cpb.20.1351 4640444
22 Flaschenträger B Bernhard K Löwenberg C Schläpfer M Über einen neuartigen Abbau der aliphatischen Kette [Translation from German: A novel degradation of the aliphatic chain]. Hoppe Seylers Z Physiol Chem. 1934; 225:157–167.http://dx.doi.org/10.1515/bchm2.1934.225.4.157
23 Zhou JQ Tang ZQ Zhang JN Tang JC Metabolism and effect of para-toluene-sulfonamide on rat liver microsomal cytochrome P450 from in vivo and in vitro studies. Acta Pharmacol Sin. 2006;27(5):635–640. http://dx.doi.org/10.1111/j.1745-7254.2006.00307.x 16626521
24 Martínez-Larrañaga MR Fernandez-Cruz ML Frejo MT Díaz MJ Martínez MA Fernandez MC Anadón A Pharmacokinetics of chloramine-T in rats. Methods Find Exp Clin Pharmacol. 1996; 18:217.
25 Anadón A Martínez-Larrañaga M Fernandez-Cruz M Morales M Anton M Frejo M Martinez M Fernandez M Brain disposition of chloramine-T and neurochemical consequences in rats. J Vet Pharmacol Ther. 1997; 20:265–266.
26 European Medicines Evaluation Agency (EMEA) Tosylchloramide sodium: Summary Report (1). London, UK: The European Agency for the Evaluation of Medicinal Products, Committee for Veterinary Medicinal Products; 1999.
27 Schafer EW The acute oral toxicity of 369 pesticidal, pharmaceutical and other chemicals to wild birds. Toxicol Appl Pharmacol. 1972; 21(3):315–330. http://dx.doi.org/10.1016/0041-008X(72)90151-2 5027965
28 United States Environmental Protection Agency (USEPA). Toxic Substance Control Act (TSCA) Section 8(e) Notices: p-Toluenesulfonamide, 70-55-3. 2011. 8EHQ-0607-16877A. https://www.epa.gov/oppt/tsca8e/pubs/8emonthlyreports/2007/8ejun2007.html [Accessed October 22, 2013]
29 United States Environmental Protection Agency (USEPA). Reproductive toxicity: Test substance (70-55-3) Benzenesulfonamide, 4-methyl-. High Production Volume Information System (HPVIS); 2011. https://iaspub.epa.gov/oppthpv/Public_Search.PublicTabs?SECTION=1&epcount=1&v_rs_list=25311106 [Accessed October 22, 2013]
30 United States Environmental Protection Agency (USEPA). Developmental toxicity/teratogenicity: Test substance (70-55-3) Benzenesulfonamide, 4-methyl-. High Production Volume Information System (HPVIS); 2011. https://iaspub.epa.gov/oppthpv/Public_Search.PublicTabs?SECTION=1&epcount=1&v_rs_list=25311127 [Accessed October 22, 2013]
31 Eckhardt K King M-T Gocke E Wild D Mutagenicity study of Remsen-Fahlberg saccharin and contaminants. Toxicol Lett. 1980; 7(1):51–60. http://dx.doi.org/10.1016/0378-4274(80)90085-5 6794189
32 United States Environmental Protection Agency (USEPA). Genetic toxicity in vitro: Test substance (70-55-3) Benzenesulfonamide, 4-methyl-. High Production Volume Information System (HPVIS); 1994. https://iaspub.epa.gov/oppthpv/Public_Search.PublicTabs?SECTION=1&epcount=2&v_rs_list=25311094,25311084 [Accessed October 22, 2013]
33 King-Herbert A Thayer K NTP workshop: animal models for the NTP rodent cancer bioassay: stocks and strains—should we switch? Toxicol Pathol. 2006; 34(6):802–805. http://dx.doi.org/10.1080/01926230600935938 17162538
34 Maronpot RR Boorman GA Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982; 10(2):71–78. http://dx.doi.org/10.1177/019262338201000210 28094716
35 Boorman GA Montgomery CA Jr Eustis SL Wolfe MJ McConnell EE Hardisty JF Quality assurance in pathology for rodent carcinogenicity studies. In: Milman HA Weisburger EKeditors. Handbook of Carcinogen Testing. Park Ridge (NJ): Noyes Publications; 1985. p. 345–357.
36 Gart JJ Chu KC Tarone RE Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979; 62(4):957–974. 285297
37 Dunnett CW A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955; 50(272):1096–1121.http://dx.doi.org/10.1080/01621459.1955.10501294
38 Williams DA The comparison of several dose levels with a zero dose control. Biometrics. 1972; 28(2):519–531. http://dx.doi.org/10.2307/2556164 5037867
39 Williams DA A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971; 27(1):103–117. http://dx.doi.org/10.2307/2528930 5547548
40 Shirley E A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977; 33(2):386–389. http://dx.doi.org/10.2307/2529789 884197
41 Williams DA A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986; 42(1):183–186. http://dx.doi.org/10.2307/2531254 3719054
42 Dunn OJ Multiple comparisons using rank sums. Technometrics. 1964; 6(3):241–252.http://dx.doi.org/10.1080/00401706.1964.10490181
43 Jonckheere A A distribution-free k-sample test against ordered alternatives. Biometrika. 1954; 41:133–145.http://dx.doi.org/10.1093/biomet/41.1-2.133
44 Dixon W Massey F Introduction to statistical analysis. 2nd ed. New York (NY): McGraw Hill Book Company Inc; 1957. p. 276–278.
45 Code of Federal Regulations (CFR). 21:Part 58.
46 Zeiger E, Anderson B, Haworth S, Lawlor T, Mortelmans K. Salmonella mutagenicity tests. 5. Results from the testing of 311 chemicals. Environ Mol Mutag. 1992; 19:2-141. http://dx.doi.org/10.1002/em.2850190603
47 Witt KL Livanos E Kissling GE Torous DK Caspary W Tice RR Recio L Comparison of flow cytometry- and microscopy-based methods for measuring micronucleated reticulocyte frequencies in rodents treated with nongenotoxic and genotoxic chemicals. Mutat Res. 2008; 649(1-2):101–113. http://dx.doi.org/10.1016/j.mrgentox.2007.08.004 17869571
48 Torous DK Hall NE Illi-Love AH Diehl MS Cederbrant K Sandelin K Pontén I Bolcsfoldi G Ferguson LR Pearson A Interlaboratory validation of a CD71-based flow cytometric method (Microflow) for the scoring of micronucleated reticulocytes in mouse peripheral blood. Environ Mol Mutagen. 2005; 45(1):44–55. 10.1002/em.20081 15605355
49 Dertinger SD, Camphausen K, MacGregor JT, Bishop ME, Torous DK, Avlasevich S, Cairns S, Tometsko CR, Menard C, Muanza T, et al. Three‐color labeling method for flow cytometric measurement of cytogenetic damage in rodent and human blood. Environ Mol Mutag. 2004; 44(5):427-435. http://dx.doi.org/10.1002/em.20075
50 MacGregor JT Bishop ME McNamee JP Hayashi M Asano N Wakata A Nakajima M Saito J Aidoo A Moore MM Flow cytometric analysis of micronuclei in peripheral blood reticulocytes: II. An efficient method of monitoring chromosomal damage in the rat. Toxicol Sci. 2006; 94(1):92–107. http://dx.doi.org/10.1093/toxsci/kfl076 16888079
51 Kissling GE Dertinger SD Hayashi M MacGregor JT Sensitivity of the erythrocyte micronucleus assay: dependence on number of cells scored and inter-animal variability. Mutat Res. 2007; 634(1-2):235–240. http://dx.doi.org/10.1016/j.mrgentox.2007.07.010 17851117
52 National Aquaculture Association (NAA). About U.S. aquaculture: What is aquaculture? 2012. https://web.archive.org/web/20130601220407/http://thenaa.net/faqs/about-us-aquaculture [Accessed October 22, 2013]
53 United States Department of Agriculture ERSU-E. Aquaculture Overview. 2012. https://www.ers.usda.gov/topics/animal-products/aquaculture.aspx [Accessed October 22, 2013]
54 Hoovers Commercial Database. Aquaculture industry overview. 2012. http://www.hoovers.com/industry-facts.aquaculture.1808.html [Accessed October 22, 2013]
55 United States Department of Agriculture (USDA). Appendix 2: Overview of U.S. livestock, poultry, and aquaculture production in 2010 and statistics on major commodities. Washington, DC: USDA; 2010. https://www.aphis.usda.gov/animal_health/animal_health_report/2010/Appendix_2.pdf.
56 Food and Drug Administration (FDA). FDA approves HALAMID aqua to treat disease in freshwater fish. Food and Drug Administration (FDA); 2014. https://web.archive.org/web/20151001181338/http://www.fda.gov/AnimalVeterinary/NewsEvents/CVMUpdates/ucm396078.htm [Accessed February 10, 2015]
57 Bio-Rad Informatics/Sadtler. “KnowItAll” Digital Infrared Libraries: Condensed Phase IR Standards Library; 2004. Spectrum SA No. 320.
58 National Institute of Advanced Industrial Science and Technology (NIAIST). Spectral Database for Organic Compounds: (SDBS)-1H NMR. Tokyo, Japan; 2004. No. 2975HSP-04-560.
59 National Institute of Advanced Industrial Science and Technology (NIAIST). Spectral Database for Organic Compounds: (SDBS)-13C NMR. Tokyo, Japan; 2004. No. 2975CDS-13-865.