# Discussion

These p-toluenesulfonamide studies were conducted in response to the nomination by the United States Food and Drug Administration (FDA) and a private individual. Toxicity of p-toluenesulfonamide was studied because it is formed from chloramine-T and found in fish when chloramine-T is used as an aquaculture disinfectant. Accordingly, there is the potential that p-toluenesulfonamide might be consumed when eating fish when chloramine-T is used as a disinfectant.

Aquaculture (fish farming) is the production of fish and shellfish for human consumption, for stocking sport fishing ponds and streams, and for enhancing wild populations of fish.^52,53^ Wild harvests of fish have reached maximum sustainable yields and the aquaculture industry is one approach to producing additional fish for the food supply. In the United States aquaculture industry, there are about 6,400 farms that have combined annual revenue of 1 billion dollars.^54^ Catfish and trout are among the major fish produced by the aquaculture industry.^55^

The United States Fish and Wildlife Service and industry sponsored studies on the use of chloramine-T in combating bacterial disease in fish in the aquaculture industry.^10^ The FDA recently approved the use of chloramine-T to treat bacterial gill disease in freshwater-reared salmonids, external columnaris disease in walleye, and external columnaris disease in freshwater-reared warm water finfish.^56^

In these NTP studies, when p-toluenesulfonamide was administered in the feed at concentrations up to 30,000 ppm for 2 weeks to male and female F344/N rats and B6C3F1/N mice and in the feed at concentrations up to 10,000 ppm for 3 months to male and female F344/NTac rats and B6C3F1/N mice there was no evidence for treatment-related mortality or treatment-related lesions.

In the 2-week studies, at 30,000 ppm there were treatment-related body weight effects (greater than 10% decreases in final mean body weights relative to control body weights) in male and female F344/N rats and mice. There were increased relative kidney weights in male F344/N rats (3,000 ppm or greater), female F344/N rats, and male mice (10,000 and 30,000 ppm), and female mice (1,500 ppm or greater). Decreased absolute organ weights were found in the: heart, liver, lung, and thymus of male F344/N rats; heart and liver of female F344/N rats; thymus of male and female mice; and liver of female mice. Most of these decreases in absolute organ weights occurred primarily at 30,000 ppm.

In the 3-month studies, the final mean body weights of F344/NTac rats exposed to 10,000 ppm were significantly lower than those of the controls; final mean body weights of other exposed groups of F344/NTac rats and all exposed groups of mice were generally similar to those of the controls. There were increased relative kidney weights and decreased absolute and relative thymus weights in male F344/NTac rats; biologically significant organ weight changes did not occur in female F344/NTac rats. In the mouse study, increased relative lung weights occurred in males and increased absolute and relative kidney weights and increased relative liver weights occurred in females. There was no evidence for reproductive organ toxicity in male F344/NTac rats or mice, and there was no evidence of treatment-related lesions in any organ in male or female F344/NTac rats or mice. No treatment-related lesions were seen in this 3-month NTP study, including no urinary bladder lesions that had been reported previously in two out of 10 male rats at 10,000 ppm in a 90-day study reviewed by the USEPA.^28^

p-Toluenesulfonamide was not mutagenic in the Salmonella typhimurium test nor did it induce micronuclei in reticulocytes or erythrocytes in peripheral blood of male or female F344/NTac rats or B6C3F1/N mice after 3 months of exposure.

Under the conditions of these 3-month feed studies, there were no treatment-related lesions in male or female F344/NTac rats or mice exposed to p-toluenesulfonamide in the feed at 625, 1,250, 2,500, 5,000, or 10,000 ppm. The most sensitive measures of p-toluenesulfonamide exposure in each species and sex were increased relative kidney weights in male F344/NTac rats [lowest observed effect level (LOEL) 2,500 ppm; 200 mg/kg], decreased body weight in female F344/NTac rats (LOEL 10,000 ppm; 780 mg/kg), increased relative lung weight in male mice (LOEL 10,000 ppm; 1,760 mg/kg), and increased relative liver weight and absolute and relative kidney weights in female mice (LOEL 10,000 ppm; 1,890 mg/kg). It is uncertain if these body weight or organ weight effects would compromise the survival or well-being of the animal after longer exposures.