# Results

## Two-week Study in F344/N Rats

All F344/N rats survived to the end of the study (Table 2). Final mean body weights and mean body weight gains of 10,000 and 30,000 ppm males and 30,000 ppm females were significantly less than those of the controls; the mean body weight gain of 10,000 ppm females was significantly less than that of the controls. Feed consumption by 10,000 and 30,000 ppm males and 30,000 ppm females was less than that by the controls throughout the study (Table 2 and G1). Exposure concentrations of 750, 1,500, 3,000, 10,000, and 30,000 ppm resulted in average daily doses of approximately 95, 185, 370, 1,170, and 3,135 mg p-toluenesulfonamide/kg body weight to males and 80, 170, 335, 1,050, and 2,645 mg/kg to females. No clinical observations or histopathologic findings were attributed to p-toluenesulfonamide exposure.

Table 2 Survival, Body Weights, and Feed Consumption of F344/N Rats in the Two-week Feed Study of p-Toluenesulfonamide^a^

Concentration (ppm) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%) | Feed Consumption Week 1 (g) | Feed Consumption Week 2 (g)
Male
0 | 5/5 | 90 ± 3 | 161 ± 5 | 71 ± 4 | | 15.5 | 16.5
750 | 5/5 | 91 ± 2 | 153 ± 6 | 62 ± 4 | 95 | 16.4 | 14.2
1,500 | 5/5 | 91 ± 2 | 161 ± 4 | 70 ± 3 | 100 | 14.6 | 16.1
3,000 | 5/5 | 93 ± 3 | 159 ± 5 | 66 ± 3 | 98 | 15.6 | 15.6
10,000 | 5/5 | 91 ± 2 | 147 ± 3* | 57 ± 2** | 91 | 12.9 | 14.8
30,000 | 5/5 | 89 ± 2 | 114 ± 2** | 25 ± 1** | 71 | 8.3 | 12.8
Female
0 | 5/5 | 90 ± 2 | 126 ± 3 | 36 ± 3 | | 12.2 | 10.5
750 | 5/5 | 89 ± 2 | 128 ± 2 | 39 ± 1 | 102 | 11.9 | 11.9
1,500 | 5/5 | 87 ± 2 | 125 ± 4 | 38 ± 3 | 100 | 12.1 | 11.8
3,000 | 5/5 | 88 ± 4 | 121 ± 2 | 33 ± 2 | 96 | 11.7 | 11.6
10,000 | 5/5 | 90 ± 3 | 118 ± 3 | 29 ± 2* | 94 | 11.0 | 10.8
30,000 | 5/5 | 90 ± 1 | 104 ± 1** | 14 ± 2** | 83 | 7.5 | 9.6

* Significantly different (P ≤ 0.05) from the control group by Williams’ test.

** P ≤ 0.01.

^a^ Weights and weight changes are given as mean ± standard error. Feed consumption is expressed as grams per animal per day.

^b^ Number of animals surviving at 15 days/number initially in group.

The absolute kidney weights were decreased in 30,000 ppm males by approximately 19%; the relative kidney weights were increased in 3,000 ppm or greater males and in 10,000 and 30,000 ppm females (Table C-1). There were no histologic findings that correlated with these organ weights changes.

Other organ weight changes in male F344/N rats included decreases in the absolute heart, liver, and thymus weights at 30,000 ppm; the absolute lung weights at 1,500 ppm or greater; and the relative lung weight at 1,500 ppm (Table C-1). The relative testis weight of 30,000 ppm males was increased. Absolute heart and liver weights were decreased in 30,000 ppm female rats. There were no histologic findings that correlated with these organ weights changes, and they are considered to be primarily related to changes in body weights.

Exposure Concentration Selection Rationale: There were no treatment-related deaths, clinical toxicity, or gross or microscopic findings in male or female F344/N rats in the 2-week p-toluenesulfonamide feed study. The primary finding was decreased body weights at 10,000 and 30,000 ppm relative to controls. Final mean body weights at 10,000 and 30,000 ppm were 9% and 29% less than controls for males and 6% and 17% less for females, respectively. The doses selected for the 3-month feed studies in F344/NTac rats were 0, 625, 1,250, 2,500, 5,000, and 10,000 ppm.

## Three-month Study in F344/NTac Rats

All core study F344/NTac rats survived to the end of the study (Table 3). The final mean body weights and the mean body weight gains of 10,000 ppm males and females were significantly less than those of the controls; in addition, the mean body weight gains of 2,500 ppm males and 5,000 ppm males and females were significantly decreased (Table 3 and Figure 3). Feed consumption by 5,000 ppm males and 10,000 ppm males and females was less than that by the controls early in the study but generally recovered to near control values later in the study (Table 3, Table G-2, Table G-3). Exposure concentrations of 625, 1,250, 2,500, 5,000, and 10,000 ppm resulted in average daily doses of approximately 50 (range 31 to 83), 100 (59 to 165), 200 (130 to 318), 380 (247 to 615), and 725 (505 to 1,553) mg p-toluenesulfonamide/kg body weight to males and 30 (36 to 76), 110 (68 to 154), 210 (138 to 294), 400 (275 to 555), and 780 (547 to 1,071) mg/kg to females. No clinical observations or histopathologic findings were attributed to p-toluenesulfonamide exposure.

Table 3 Survival, Body Weights, and Feed Consumption of F344/NTac Rats in the Three-month Feed Study of p-Toluenesulfonamide^a^

Concentration (ppm) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%) | Feed Consumption Week 1 (g) | Feed Consumption Week 14 (g)
Male
0 | 10/10 | 87 ± 3 | 339 ± 7 | 252 ± 6 | | 16.2 | 16.6
625 | 10/10 | 87 ± 4 | 325 ± 5 | 237 ± 4 | 96 | 16.4 | 16.1
1,250 | 10/10 | 89 ± 3 | 338 ± 6 | 249 ± 6 | 100 | 16.6 | 16.0
2,500 | 10/10 | 89 ± 3 | 323 ± 7 | 234 ± 6* | 95 | 15.5 | 16.9
5,000 | 10/10 | 87 ± 3 | 320 ± 6 | 233 ± 6* | 94 | 14.1 | 16.7
10,000 | 10/10 | 87 ± 3 | 315 ± 8* | 228 ± 7** | 93 | 13.2 | 15.9
Female
0 | 10/10 | 83 ± 2 | 190 ± 3 | 107 ± 3 | | 12.1 | 10.3
625 | 10/10 | 86 ± 2 | 190 ± 2 | 104 ± 2 | 100 | 12.8 | 10.8
1,250 | 10/10 | 85 ± 2 | 187 ± 4 | 103 ± 3 | 99 | 13.0 | 10.2
2,500 | 10/10 | 84 ± 2 | 187 ± 2 | 102 ± 3 | 98 | 12.3 | 10.3
5,000 | 10/10 | 86 ± 2 | 184 ± 3 | 98 ± 3* | 97 | 11.6 | 10.1
10,000 | 10/10 | 85 ± 2 | 174 ± 2** | 90 ± 2** | 92 | 10.6 | 9.6

* Significantly different (P ≤ 0.05) from the control group by Williams’ or Dunnett’s test.

** Significantly different (P ≤ 0.01) from the control group by Williams’ test.

^a^ Weights and weight changes are given as mean ± standard error. Feed consumption is expressed as grams per animal per day.

^b^ Number of animals surviving at 14 weeks/number initially in group.

Figure 3

Growth Curves for F344/NTac Rats Exposed to p-Toluenesulfonamide in Feed for Three Months

A few scattered changes occurred in the hematology and clinical chemistry data for F344/NTac rats (Table B-1). These changes were minor (exposed groups were often ≤5% different from the controls) and mostly sporadic or inconsistent between exposure concentrations, timepoints, and/or sexes; all would have been considered within biological variability. Thus, no clinical pathology changes detected statistically for male or female F344/NTac rats were considered biologically significant or toxicologically relevant to the administration of p-toluenesulfonamide.

Absolute and relative thymus weights of 10,000 ppm males were significantly less by approximately 22% compared to those of the controls (Table 4, Table C-2). Relative kidney weights were increased in 2,500 ppm or greater males, and were up to approximately 14% greater than the controls in the 10,000 ppm group. Corresponding histologic lesions were not observed in the kidney or thymus. The mean absolute heart weight of 10,000 ppm females was decreased by approximately 8%, which was attributed to a similar decrease in mean body weight of that group compared to controls (Table C-2).

Table 4 Selected Organ Weights and Organ-Weight-to-Body-Weight Ratios for Male F344/NTac Rats in the Three-month Feed Study of p-Toluenesulfonamide^a^

| 0 ppm | 625 ppm | 1,250 ppm | 2,500 ppm | 5,000 ppm | 10,000 ppm
n | 10 | 10 | 10 | 10 | 10 | 10
Necropsy body wt | 339 ± 7 | 325 ± 5 | 338 ± 6 | 323 ± 7 | 320 ± 6 | 315 ± 8*
R. Kidney
Absolute | 1.05 ± 0.02 | 1.05 ± 0.01 | 1.08 ± 0.02 | 1.10 ± 0.03 | 1.12 ± 0.03 | 1.11 ± 0.03
Relative | 3.10 ± 0.04 | 3.25 ± 0.06 | 3.19 ± 0.05 | 3.42 ± 0.04** | 3.51 ± 0.04** | 3.54 ± 0.06**
Thymus
Absolute | 0.303 ± 0.012 | 0.270 ± 0.012 | 0.285 ± 0.009 | 0.267 ± 0.009 | 0.273 ± 0.009^b^ | 0.237 ± 0.014**
Relative | 0.893 ± 0.029 | 0.829 ± 0.029 | 0.845 ± 0.025 | 0.834 ± 0.044 | 0.850 ± 0.021^b^ | 0.754 ± 0.042*

* Significantly different (P ≤ 0.05) from the control group by Dunnett’s test.

** Significantly different (P ≤ 0.01) from the control group by Williams’ test.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

^b^ n=9.

Male F344/NTac rats exposed to p-toluenesulfonamide did not display any biologically significant changes in epididymis or testis weights, epididymal sperm counts, sperm motility, or testicular spermatid counts (Table D-1). These data indicate that p-toluenesulfonamide exposure via dietary administration does not exhibit the potential to be a reproductive toxicant in male F344/NTac rats. Vaginal lavage slide quality precluded assessment of estrous cyclicity and statistical analyses in female F344/NTac rats.

## Two-week Study in Mice

All mice survived to the end of the study (Table 5). Final mean body weights and mean body weight gains of 30,000 ppm males and females were significantly less than those of the controls; these groups lost weight during the study. The mean body weight gains of all remaining exposed groups of females were significantly less than those of the controls. Feed consumption by exposed groups of mice was generally similar to that by the controls throughout the study (Table 5, Table G-4). Exposure concentrations of 750, 1,500, 3,000, 10,000, and 30,000 ppm resulted in average daily doses of approximately 150, 300, 700, 2,035, and 7,690 mg p-toluenesulfonamide/kg body weight to males and 125, 280, 635, 2,410, and 6,000 mg/kg to females. No clinical observations or histopathologic findings were attributed to p-toluenesulfonamide exposure.

Table 5 Survival, Body Weights, and Feed Consumption of Mice in the Two-week Feed Study of p-Toluenesulfonamide^a^

Concentration (ppm) | Survival^b^ | Initial Body Weight (g) | Final Body Weight(g) | Change in Body Weight (g) | Final Weight Relative to Controls (%) | Feed Consumption Week 1 (g) | Feed Consumption Week 2 (g)
Male
0 | 5/5 | 22.1 ± 0.6 | 24.6 ± 0.5 | 2.5 ± 0.3 | – | 5.1 | 4.6
750 | 5/5 | 22.5 ± 0.7 | 24.7 ± 0.6 | 2.2 ± 0.4 | 100 | 5.0 | 4.4
1,500 | 5/5 | 22.4 ± 0.5 | 23.9 ± 0.9 | 1.5 ± 0.5 | 97 | 4.1 | 5.2
3,000 | 5/5 | 22.7 ± 0.5 | 24.8 ± 0.4 | 2.1 ± 0.2 | 101 | 5.8 | 5.3
10,000 | 5/5 | 22.3 ± 0.4 | 23.9 ± 0.3 | 1.5 ± 0.2 | 97 | 4.7 | 4.7
30,000 | 5/5 | 22.1 ± 0.6 | 21.2 ± 0.5** | −0.9 ± 0.2** | 86 | 5.2 | 5.9
Female
0 | 5/5 | 16.9 ± 0.3 | 19.6 ± 0.5 | 2.7 ± 0.2 | – | 3.5 | 3.9
750 | 5/5 | 17.2 ± 0.3 | 19.3 ± 0.2 | 2.1 ± 0.3* | 98 | 3.0 | 3.1
1,500 | 5/5 | 17.3 ± 0.2 | 18.5 ± 0.2 | 1.2 ± 0.2** | 94 | 3.3 | 3.4
3,000 | 5/5 | 17.0 ± 0.4 | 19.0 ± 0.4 | 2.1 ± 0.2** | 97 | 4.0 | 3.6
10,000 | 5/5 | 17.4 ± 0.4 | 19.1 ± 0.4 | 1.6 ± 0.2** | 97 | 5.1 | 3.7
30,000 | 5/5 | 16.9 ± 0.3 | 16.6 ± 0.4** | −0.3 ± 0.1** | 85 | 3.0 | 3.7

* Significantly different (P ≤ 0.05) from the control group by Williams’ test.

** P ≤ 0.01.

^a^ Weights and weight changes are given as mean ± standard error. Feed consumption is expressed as grams per animal per day.

^b^ Number of animals surviving at 15 days/number initially in group.

Absolute kidney weights of 10,000 and 30,000 ppm females were increased by approximately 15% and 8%, respectively, compared to those of the controls (Table C-3). Relative kidney weights were increased in 1,500 ppm or greater females and in 10,000 and 30,000 ppm males compared to those in the controls. The 30,000 ppm males and females had mean body weight decreases of approximately 14% and 15%, respectively, compared to those of the controls. There were no histological findings that correlated with these changes in kidney weights.

Other changes in organ weights included increases in relative heart weights of 10,000 ppm females and 30,000 ppm males and females; an increase in the relative lung weight of 30,000 ppm males; an increase in the relative testis weight of 30,000 ppm males; a decrease in the absolute liver weight of 30,000 ppm females; and decreases in the absolute thymus weights of 30,000 ppm males and females and relative thymus weight of 30,000 ppm males (Table C-3). There were no histologic findings that correlated with these organ weights changes, and they are considered to be primarily related to changes in body weights.

Exposure Concentration Selection Rationale: There were no treatment-related deaths, clinical toxicity, or gross or microscopic findings in male or female B6C3F1/N mice in the 2-week p-toluenesulfonamide feed study. The primary finding was decreased body weight at 30,000 ppm relative to controls. Body weights at 30,000 ppm were 14% less for male mice and 15% less for female mice. The doses selected for the 3-month feed studies in mice were 0, 625, 1,250, 2,500, 5,000, and 10,000 ppm.

## Three-month Study in Mice

All male mice survived to the end of the study; one 10,000 ppm female mouse died during week 6 of an accidental death (Table 6). The mean body weight gains of 5,000 and 10,000 ppm males were significantly less than those of the controls; the final mean body weight and mean body weight gain of 1,250 ppm females were significantly greater than those of the controls (Table 6 and Figure 4). Feed consumption by 625 and 1,250 ppm males was greater than that by the controls early in the study but returned to near control values later in the study; feed consumption by exposed groups of females was generally similar to that by the controls throughout the study (Table 6, Table G-5, Table G-6). Exposure concentrations of 625, 1,250, 2,500, 5,000, and 10,000 ppm resulted in average daily doses of approximately 120 (range 86 to 169), 230 (158 to 312), 420 (351 to 533), 770 (666 to 1,437), and 1,760 (1,391 to 2,458) mg p-toluenesulfonamide/kg body weight to males and 90 (84 to 105), 210 (176 to 246), 380 (313 to 469), 780 (684 to 885), and 1,890 (1,718 to 2,215) mg/kg to females. No clinical observations or histopathologic findings were attributed to p-toluenesulfonamide exposure.

Table 6 Survival, Body Weights, and Feed Consumption of Mice in the Three-month Feed Study of p-Toluenesulfonamide^a^

Concentration (ppm) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%) | Feed Consumption Week 1 (g) | Feed Consumption Week 14 (g)
Male
0 | 10/10 | 22.2 ± 0.3 | 32.1 ± 0.7 | 9.9 ± 0.5 | | 4.3 | 4.3
625 | 10/10 | 22.3 ± 0.4 | 31.8 ± 0.9 | 9.6 ± 0.6 | 99 | 5.8 | 4.4
1,250 | 10/10 | 22.7 ± 0.4 | 32.4 ± 1.1 | 9.7 ± 0.8 | 101 | 5.8 | 4.1
2,500 | 10/10 | 22.7 ± 0.4 | 31.7 ± 0.9 | 9.0 ± 0.7 | 99 | 4.7 | 4.5
5,000 | 10/10 | 22.7 ± 0.4 | 30.8 ± 0.8 | 8.1 ± 0.5* | 96 | 4.1 | 4.1
10,000 | 10/10 | 22.4 ± 0.4 | 30.0 ± 0.7 | 7.6 ± 0.5* | 93 | 4.8 | 4.4
Female
0 | 10/10 | 18.4 ± 0.2 | 24.8 ± 0.5 | 6.3 ± 0.4 | | 3.4 | 3.6
625 | 10/10 | 18.7 ± 0.2 | 26.7 ± 0.6 | 8.1 ± 0.5 | 108 | 3.2 | 3.6
1,250 | 10/10 | 18.7 ± 0.2 | 27.1 ± 0.5* | 8.3 ± 0.5* | 109 | 3.8 | 3.8
2,500 | 10/10 | 18.7 ± 0.2 | 26.4 ± 0.6 | 7.7 ± 0.5 | 107 | 3.6 | 3.3
5,000 | 10/10 | 18.8 ± 0.2 | 25.4 ± 0.5 | 6.7 ± 0.6 | 103 | 3.4 | 3.5
10,000 | 9/10^c^ | 18.5 ± 0.3 | 24.8 ± 0.7 | 6.2 ± 0.5 | 100 | 3.6 | 4.6

* Significantly different (P ≤ 0.05) from the control group by Williams’ or Dunnett’s test.

^a^ Weights and weight changes are given as mean ± standard error. Feed consumption is expressed as grams per animal per day.

^b^ Number of animals surviving at 14 weeks/number initially in group.

^c^ Week of death: 6.

Figure 4

Growth Curves for Mice Exposed to p-Toluenesulfonamide in Feed for Three Months

No changes attributable to the administration of p-toluenesulfonamide occurred in the hematology data for male or female mice (Table B-2).

Female mice exposed to 10,000 ppm had increased absolute (approximately 13%) and relative (approximately 14%) kidney weights compared to those of the controls (Table 7, Table C-4). Relative lung weight was increased by approximately 27% in 10,000 ppm males, and relative liver weight was increased by approximately 10% in 10,000 ppm females. The mean body weight of 10,000 ppm males was approximately 7% less than that of the control group at necropsy, but there was no difference between 10,000 ppm females and the control group at necropsy. Corresponding changes were not observed histologically. Other changes in organ weights were not considered to be biologically significant.

Table 7 Selected Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice in the Three-month Feed Study of p-Toluenesulfonamide^a^

| 0 ppm | 625 ppm | 1,250 ppm | 2,500 ppm | 5,000 ppm | 10,000 ppm
Male
n | 10 | 10 | 10 | 10 | 10 | 10
Necropsy body wt | 32.1 ± 0.7 | 31.8 ± 0.9 | 32.4 ± 1.1 | 31.7 ± 0.9 | 30.8 ± 0.8 | 30.0 ± 0.7
Lung
Absolute | 0.21 ± 0.02 | 0.22 ± 0.02 | 0.23 ± 0.01 | 0.20 ± 0.01 | 0.23 ± 0.02 | 0.25 ± 0.02
Relative | 6.51 ± 0.52 | 6.80 ± 0.40 | 7.12 ± 0.32 | 6.35 ± 0.21 | 7.45 ± 0.48 | 8.24 ± 0.51*
Female
n | 10 | 10 | 10 | 10 | 10 | 9
Necropsy body wt | 24.8 ± 0.5 | 26.7 ± 0.6 | 27.1 ± 0.5* | 26.4 ± 0.6 | 25.4 ± 0.5 | 24.8 ± 0.7
R. Kidney
Absolute | 0.16 ± 0.00 | 0.16 ± 0.00 | 0.17 ± 0.00 | 0.16 ± 0.01 | 0.17 ± 0.00 | 0.18 ± 0.01**
Relative | 6.42 ± 0.15 | 6.14 ± 0.12 | 6.23 ± 0.13 | 6.08 ± 0.15 | 6.61 ± 0.12 | 7.31 ± 0.16**
Liver
Absolute | 1.02 ± 0.02 | 1.13 ± 0.02* | 1.15 ± 0.03** | 1.09 ± 0.03 | 1.07 ± 0.03 | 1.12 ± 0.04
Relative | 41.14 ± 0.87 | 42.36 ± 0.61 | 42.61 ± 0.63 | 41.44 ± 0.92 | 42.01 ± 0.47 | 45.15 ± 1.03**

* Significantly different (P ≤ 0.05) from the control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Male mice exposed to p-toluenesulfonamide did not display any biologically significant changes in epididymis or testis weights, epididymal sperm counts, sperm motility, or testicular spermatid counts (Table D-2). These data indicate that p-toluenesulfonamide exposure via dietary administration does not exhibit the potential to be a reproductive toxicant in male B6C3F1/N mice. Vaginal lavage slide quality precluded assessment of estrous cyclicity and statistical analyses in female B6C3F1/N mice.

## Genetic Toxicology

p-Toluenesulfonamide (33 to 10,000 μg/plate, dissolved in acetone) was tested in three strains of Salmonella typhimurium (TA98, TA100, and TA102), with and without 10% induced rat liver S9 enzymes; no mutagenicity was observed in any of the three bacterial strains, with or without S9 activation enzymes (Table E-1).

In vivo, no increases in micronucleated reticulocytes (polychromatic erythrocytes) or erythrocytes (normochromatic erythrocytes) were observed in peripheral blood of male or female F344/NTac rats or B6C3F1/N mice from the 3-month studies (Table E-2 and Table E-3). No biologically significant changes in the percentage of reticulocytes among total erythrocytes were seen in either of these micronucleus studies, suggesting that p-toluenesulfonamide did not induce bone marrow toxicity. Small but statistically significant (P < 0.025) increases in the percentage of reticulocytes were observed in male mice (pairwise test) and male rats (trend test), but the values in each case were within normal ranges, the increases that were observed were quite small, and the increases in percentage of reticulocytes were judged to be equivocal.