# Materials and Methods

## Procurement and Characterization of p-Toluenesulfonamide

p-Toluenesulfonamide was obtained from Acros Organics (Geel, Belgium) in one lot (A009615201). Lot A009615201 was purified by Battelle’s Organic Synthesis Group (Columbus, OH) and was renamed lot 112003. Lot 112003 was used in the 2-week and 3-month studies. Identity and purity analyses were conducted by the analytical chemistry laboratory at Battelle Columbus Operations (Columbus, OH) (Appendix F). In addition, Karl Fischer titration and elemental analyses were performed by Prevalere Life Sciences, Inc. (Whitesboro, NY). Reports on analyses performed in support of the p-toluenesulfonamide studies are on file at the National Institute of Environmental Health Sciences.

Lot 112003, a white crystalline chemical, was identified as p-toluenesulfonamide using infrared and proton and carbon-13 nuclear magnetic resonance (NMR) spectroscopy and by melting point analysis.

The purity of the bulk chemical was determined by elemental analyses, differential scanning calorimetry, and high-performance liquid chromatography with ultraviolet detection (HPLC/UV). Tentative impurity identification was obtained using mass spectrometry (MS) and proton and carbon-13 NMR spectroscopy.

Karl Fischer titration indicated approximately 0.1% water. Elemental analyses for carbon, hydrogen, and nitrogen were in agreement with the theoretical values for p-toluenesulfonamide. Differential scanning calorimetry indicated a purity of 100%. HPLC/UV indicated one major peak and one reportable impurity with an individual area equal to 0.2% of the total peak area. The most probable structure for the impurity based on MS and NMR analyses was 4-methyl-N-phenylbenzene sulfonamide, although the impurity peak in the HPLC/UV analyses might have been composed of multiple components. The overall purity of lot 112003 was determined to be greater than 99%.

To ensure stability, the bulk chemical was stored under a headspace of inert gas at room temperature, protected from light. Periodic reanalyses of the bulk chemical were performed at the study laboratory at BioReliance Corporation (Rockville, MD) during the 2-week and 3-month studies using HPLC/UV, and no degradation of the bulk chemical was detected.

## Preparation and Analysis of Dose Formulations

The dose formulations were prepared once during the 2-week studies and eight times during the 3-month studies by mixing p-toluenesulfonamide with feed. A premix was prepared by hand and then blended with additional feed in a Patterson-Kelly twin-shell blender. Formulations were stored in doubled polyethylene bags sealed with twist ties protected from light at room temperature for up to 42 days.

Homogeneity studies of the 750 and 30,000 ppm dose formulations and stability studies of the 750 ppm dose formulation were performed by the analytical chemistry laboratory using HPLC/UV. An additional homogeneity study of the 625 ppm dose formulation was performed by the study laboratory using HPLC/UV. Homogeneity was confirmed, and stability was confirmed for at least 42 days for dose formulations stored in plastic zip-lock bags, protected from light, at temperatures up to room temperature, and for at least 7 days for dose formulations kept in glass feeding containers without urine and feces under simulated animal room conditions.

Periodic analyses of the dose formulations of p-toluenesulfonamide were conducted by the study laboratory using HPLC/UV. During the 2-week studies, the dose formulations were analyzed once; all 10 dose formulations for rats and mice were within 10% of the target concentrations (Table F-3). Animal room samples of these dose formulations were also analyzed; all 10 for male rats and two of 10 for female mice were within 10% of the target concentrations. During the 3-month studies, the dose formulations were analyzed three times; animal room samples of these dose formulations were also analyzed (Table F-4). Of the dose formulations analyzed, all 34 for rats and mice were within 10% of the target concentrations; 15 of 30 animal room samples for rats and 13 of 30 for mice were within 10% of the target concentrations. Low recovery of p-toluenesulfonamide in many of the animal room samples was attributed to potential contamination of dosed feed with urine and/or feces, which may have caused irreversible binding of the test chemical to the feed. A similar behavior was observed in the simulated animal room stability studies conducted on the 750 ppm dose formulation by the analytical chemistry laboratory where a decline of formulation concentration was observed in the presence of urine and feces.

## Animal Source

Male and female F344/N rats and B6C3F1/N mice were obtained from the NTP colony maintained at Taconic Farms, Inc. (Germantown, NY), for the 2-week studies. For the 3-month studies, male and female F344/NTac rats were obtained from the commercial colony at Taconic Farms, Inc.; B6C3F1/N mice were obtained from the NTP colony maintained at Taconic Farms, Inc. The rationale for change of rat strain from F344/N to F344/NTac was a programmatic decision. For many years, NTP used the inbred F344/N rat for its toxicity and carcinogenicity studies. Over a period of time, the F344/N rat exhibited sporadic seizures and idiopathic chylothorax, and consistently high rates of mononuclear cell leukemia and testicular neoplasia. Because of these issues in the F344/N rat and the NTP’s desire to find a more fecund rat model that could be used in both reproductive and carcinogenesis studies for comparative purposes, a change in the rat model was explored. Following a workshop in 2005, the F344 rat from the Taconic commercial colony (F344/NTac) was used for a few NTP studies to allow NTP to evaluate different rat models. The F344/NTac rat was used in four subchronic, including the current 3-month study, and two chronic studies between 2005 and 2006.^33^

## Animal Welfare

Animal care and use are in accordance with the Public Health Service Policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by the Association for the Assessment and Accreditation of Laboratory Animal Care International. Studies were approved by the BioReliance Corporation Animal Care and Use Committee and conducted in accordance with all relevant NIH and NTP animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Two-week Studies

The oral gavage LD_50_ of p-toluenesulfonamide is 2,330 mg/kg body weight in F344/N rats. Doses selected for the 2-week feed studies were 0, 750, 1,500, 3,000, 10,000, and 30,000 ppm, with the high dose estimated to deliver approximately 3,000 mg/kg in feed.

On receipt, F344/N rats were 3 weeks old, and mice were 3 to 4 weeks old. Animals were quarantined for 13 (F344/N rats) or 14 (mice) days. F344/N rats were 5 weeks old and mice were 5 to 6 weeks old on the first day of the studies. Before the studies began, five male and five female F344/N rats were randomly selected for parasite evaluation and gross observation for evidence of disease. All results were negative.

Groups of five male and five female F344/N rats and mice were fed diets containing 0, 750, 1,500, 3,000, 10,000, or 30,000 ppm p-toluenesulfonamide for 15 days. Feed and water were available ad libitum. F344/N rats and female mice were housed five per cage; male mice were housed individually. Animals were observed twice daily. The animals were weighed and clinical findings were recorded initially, on day 8, and at the end of the studies; feed consumption was recorded on day 8 and at the end of the studies. Details of the study design and animal maintenance are summarized in Table 1.

Table 1 Experimental Design and Materials and Methods in the Feed Studies of p-Toluenesulfonamide

Two-week Studies | Three-month Studies
Study Laboratory
BioReliance Corporation (Rockville, MD) | BioReliance Corporation (Rockville, MD)
Strain and Species
F344/N rats | F344/NTac rats
B6C3F1/N mice | B6C3F1/N mice
Animal Source
Taconic Farms, Inc. (Germantown, NY) | Taconic Farms, Inc. (Germantown, NY)
Time Held Before Studies
F344/N rats: 13 days | F344/NTac rats: 12 (males) or 13 (females) days
Mice: 14 days | Mice: 16 (males) or 17 (females) days
Average Age When Studies Began
F344/N rats: 5 weeks | F344/NTac rats: 5 to 6 weeks
Mice: 5 to 6 weeks | Mice: 7 to 8 weeks
Date of First Exposure
F344/N rats: July 5, 2006 | F344/NTac rats: October 17 (males) or 18 (females), 2006
Mice: July 6, 2006 | Mice: October 19 (males) or 20 (females), 2006
Duration of Exposure
15 days | Core study F344/NTac rats and mice: 14 weeks
| Clinical pathology study F344/NTac rats: 22 days
Date of Last Exposure
F344/N rats: July 19, 2006 | Core study F344/NTac rats: January 16 (males) or 17 (females), 2007
Mice: July 20, 2006 | Mice: January 18 (males) or 19 (females), 2007
Necropsy Dates
F344/N rats: July 19, 2006 | Core study F344/NTac rats: January 16 (males) or 17 (females), 2007
Mice: July 20, 2006 | Mice: January 18 (males) or 19 (females), 2007
Average Age at Necropsy
F344/N rats: 7 weeks | F344/NTac rats: 18 to 19 weeks
Mice: 7 to 8 weeks | Mice: 20 to 21 weeks
Size of Study Groups
5 males and 5 females | 10 males and 10 females
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights. | Same as 2-week studies
Animals per Cage
F344/N rats: 5 | F344/NTac rats: 5
Mice: 1 (males) or 5 (females) | Mice: 1 (males) or 5 (females)
Method of Animal Identification
Tail tattoo | Same as 2-week studies
Diet
Irradiated NTP-2000 open formula meal diet (Zeigler Brothers, Inc., Gardners, PA), available ad libitum | Same as 2-week studies
Water
Tap water (Washington Suburban Sanitary Commission Potomac Plant) via automatic watering system (Edstrom Industries, Waterford, WI); available ad libitum | Same as 2-week studies
Cages
Polycarbonate (Lab Products, Inc., Seaford, DE), changed twice per week for F344/N rats and female mice and once weekly for male mice | Same as 2-week studies
Bedding
Irradiated heat-treated Sani-Chips^®^ hardwood chips (P.J. Murphy Forest Products Corp., Montville, NJ), changed at least twice per week for F344/N rats and female mice and once weekly for male mice | Same as 2-week studies
Cage Filters
Omnishield Paper, Remay 2024 (Dupont), Harlan Teklad, (Indianapolis, IN), changed every 2 weeks | Same as 2-week studies
Racks
Stainless steel (Lab Products, Inc., Seaford, DE); changed every 2 weeks | Same as 2-week studies
Animal Room Environment
Temperature: 72° ± 3°F | Same as 2-week studies
Relative humidity: 50% ± 15%
Room fluorescent light: 12 hours/day
Room air changes: at least 10/hour
Exposure Concentrations
0, 750, 1,500, 3,000, 10,000, or 30,000 ppm in feed, available ad libitum | 0, 625, 1,250, 2,500, 5,000, or 10,000 ppm in feed, available ad libitum
Type and Frequency of Observation
Observed twice daily; animals were weighed and clinical findings were recorded initially, on day 8, and at the end of the studies. Feed consumption was recorded on day 8 and at the end of the studies. | Observed twice daily; core study animals were weighed and clinical findings were recorded initially, on day 8, weekly thereafter, and at the end of the studies; feed consumption was recorded on day 8 and weekly thereafter.
Method of Euthanasia
Carbon dioxide asphyxiation | Same as 2-week studies
Necropsy
Necropsies were performed on all animals. Organs weighed were heart, right kidney, liver, lung, right testis, and thymus. | Necropsies were performed on all core study animals. Organs weighed were heart, right kidney, liver, lung, right testis, and thymus.
Clinical Pathology
None | Blood was collected from the retroorbital sinus of clinical pathology F344/NTac rats on days 3 and 22 and from core study animals at the end of the studies for hematology and clinical chemistry (F344/NTac rats only). Hematology: hematocrit; hemoglobin; erythrocyte, reticulocyte, and platelet counts; mean cell volume; mean cell hemoglobin; mean cell hemoglobin concentration; and leukocyte counts and differentials. Clinical chemistry: urea nitrogen, creatinine, total protein, albumin, alanine aminotransferase, alkaline phosphatase, creatine kinase, sorbitol dehydrogenase, and bile acids
Histopathology
Histopathology was performed on 0, 10,000, and 30,000 ppm F344/N rats and mice. In addition to gross lesions and tissue masses the heart, right kidney, liver, lung, right testis, and thymus were examined; the right kidney was also examined in 1,500 and 3,000 ppm female mice. | Complete histopathology was performed on 0 and 10,000 ppm core study F344/NTac rats and mice. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone with marrow, brain, clitoral gland, esophagus, eyes, gallbladder (mice), Harderian gland, heart and aorta, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, larynx (mice), liver, lung and mainstem bronchi, lymph nodes (mandibular and mesenteric), mammary gland, nose, pharynx (mice), ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, seminal vesicle, skin, spleen, stomach (forestomach and glandular), testis with epididymis, thymus, thyroid gland, tongue, trachea, urinary bladder, and uterus.
Sperm Motility and Vaginal Cytology
None | At the end of the studies, spermatid and sperm samples were collected from male animals in the 0, 2,500, 5,000, and 10,000 ppm groups. The following parameters were evaluated: spermatid heads per testis and per gram testis, sperm motility, and sperm per cauda epididymis and per gram cauda epididymis. The left cauda, left epididymis, and left testis were weighed. Vaginal samples were collected for up to 12 consecutive days prior to the end of the studies from females exposed to 0, 2,500, 5,000, or 10,000 ppm for vaginal cytology evaluations.

Necropsies were performed on all F344/N rats and mice. The heart, right kidney, liver, lung, right testis, and thymus from each animal were weighed. Histopathologic examinations of the tissues weighed were performed on 0, 10,000, and 30,000 ppm F344/N rats and mice; also, histopathologic examinations of the right kidney were performed on 1,500 and 3,000 ppm female mice. Table 1 lists the tissues and organs examined.

## Three-month Studies

On receipt, F344/NTac rats (the rat strain in use by NTP at the time of these studies) were 3 to 4 weeks old and mice were 5 to 6 weeks old. Animals were quarantined for 12 (male rats), 13 (female rats), 16 (male mice), or 17 (female mice) days. F344/NTac rats were 5 to 6 weeks old and mice were 7 to 8 weeks old on the first day of the studies. Before the studies began, five male and five female F344/NTac rats and mice were randomly selected for parasite evaluation and gross observation for evidence of disease. Serologic analyses were performed on five male and five female control F344/NTac rats and five male and five female sentinel mice at the end of the studies using the protocols of the NTP Sentinel Animal Program (Appendix I). All results were negative.

Groups of 10 male and 10 female F344/NTac rats and mice were fed diets containing 0, 625, 1,250, 2,500, 5,000, or 10,000 ppm p-toluenesulfonamide for 14 weeks. Groups of 10 male and 10 female clinical pathology F344/NTac rats were exposed to the same concentrations for 22 days. Feed and water were available ad libitum. F344/NTac rats and female mice were housed five per cage; male mice were housed individually. Animals were observed twice daily. The animals were weighed and clinical observations were recorded initially, on day 8, weekly thereafter, and at the end of the studies. Feed consumption was recorded on day 8 and weekly thereafter. Details of the study design and animal maintenance are summarized in Table 1. Information on the feed composition and contaminants is provided in Appendix H.

Animals were anesthetized with a 70%:30% CO_2_:O_2_ mixture and blood was collected from the retroorbital plexus (F344/NTac rats) or retroorbital sinus (mice) of clinical pathology rats on days 3 and 22 and of core study F344/NTac rats and mice at the end of the studies for hematology and clinical chemistry (F344/NTac rats only) analyses. For hematology, blood was placed in tubes containing dipotassium EDTA as the anticoagulant. For clinical chemistry, blood was placed in tubes devoid of anticoagulant, allowed to clot, and the serum was harvested for analysis. All clinical pathology evaluations were performed at Analytics, Inc. (Gaithersburg, MD). The hematology analyses were conducted using an ABX Pentra 60 C+ Analyzer (HORIBA Instruments Inc., Irvine, CA) using reagents supplied by the manufacturer. Clinical chemistry analyses were completed using a Hitachi 717 Analyzer (Boehringer Mannheim, Indianapolis, IN) using reagents obtained from Randox Laboratories (Oceanside, CA) or Sigma Diagnostics (St. Louis, MO). All hematology and clinical chemistry parameters evaluated are listed in Table 1.

At the end of the 3-month studies, samples were collected for sperm motility and vaginal cytology evaluations on F344/NTac rats and mice exposed to 0, 2,500, 5,000, or 10,000 ppm. The parameters evaluated are listed in Table 1. For 12 consecutive days prior to scheduled terminal euthanasia, the vaginal vaults of the females were moistened with saline, if necessary, and samples of vaginal fluid and cells were stained. Relative numbers of leukocytes, nucleated epithelial cells, and large squamous epithelial cells were determined and used to ascertain estrous cycle stage (i.e., diestrus, proestrus, estrus, and metestrus). Vaginal cytology slides were assessed in accordance with the NTP Guideline for the Cytological Staging of Rat and Mouse Estrous Cycle. Male animals were evaluated for sperm count and motility. The left testis and left epididymis were isolated and weighed. The tail of the epididymis (cauda epididymis) was then removed from the epididymal body (corpus epididymis) and weighed. Test yolk (F344/NTac rats) or modified Tyrode’s buffer (mice) was applied to slides and a small incision was made at the distal border of the cauda epididymis. The sperm effluxing from the incision were dispersed in the buffer on the slides, and the numbers of motile and nonmotile spermatozoa were counted for five fields per slide by two observers. Following completion of sperm motility estimates, each left cauda epididymis was placed in buffered saline solution. Caudae were finely minced, and the tissue was incubated in the saline solution and then heat fixed at 65°C. Sperm density was then determined microscopically with the aid of a hemacytometer. To quantify spermatogenesis, the testicular spermatid head count was determined by removing the tunica albuginea and homogenizing the left testis in phosphate-buffered saline containing 10% dimethyl sulfoxide. Homogenization-resistant spermatid nuclei were counted with a hemacytometer.

Necropsies were performed on all core study F344/NTac rats and mice. The heart, right kidney, liver, lung, right testis, and thymus from each animal were weighed. Tissues for microscopic examination were fixed and preserved in 10% neutral buffered formalin (except eyes were first fixed in Davidson’s solution), processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin. Complete histopathologic examinations were performed on all 0 and 10,000 ppm core study F344/NTac rats and mice. Table 1 lists the tissues and organs routinely examined.

After a review of the laboratory reports and selected histopathology slides by a quality assessment (QA) pathologist, the findings and reviewed slides were submitted to a NTP Pathology Working Group (PWG) coordinator for a second independent review. Any inconsistencies in the diagnoses made by the study laboratory and QA pathologists were resolved by the NTP pathology peer review process. Final diagnoses for reviewed lesions represent a consensus of the PWG or a consensus between the study laboratory pathologist, NTP pathologist, QA pathologist(s), and the PWG coordinator. Details of these review procedures have been described, in part, by Maronpot and Boorman^34^ and Boorman et al.^35^

## Statistical Methods

### Calculation and Analysis of Lesion Incidences

The incidences of nonneoplastic lesions are presented in Appendix A as the numbers of animals bearing such lesions at a specific anatomic site and the numbers of animals with that site examined microscopically. The Fisher exact test,^36^ a procedure based on the overall proportion of affected animals, was used to determine significance.

### Analysis of Continuous Variables

Two approaches were employed to assess the significance of pairwise comparisons between exposed and control groups in the analysis of continuous variables. Organ and body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^37^ and Williams.^38,39^ Hematology, clinical chemistry, spermatid, and epididymal spermatozoal data, which have typically skewed distributions, were analyzed using the nonparametric multiple comparison methods of Shirley^40^ (as modified by Williams^41^) and Dunn.^42^ Jonckheere’s test^43^ was used to assess the significance of the dose-related trends and to determine whether a trend-sensitive test (Williams’ or Shirley’s test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic dose-related trend (Dunnett’s or Dunn’s test). Prior to statistical analysis, extreme values identified by the outlier test of Dixon and Massey^44^ were examined by NTP personnel, and implausible values were eliminated from the analysis.

## Quality Assurance Methods

The 3-month studies were conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations.^45^ In addition, as records from the 3-month studies were submitted to the NTP Archives, these studies were audited retrospectively by an independent QA contractor. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Toxicity Study Report. Audit procedures and findings are presented in the reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this Toxicity Study Report.

## Genetic Toxicology

### Salmonella typhimurium Mutagenicity Test Protocol

Testing procedures used for p-toluenesulfonamide followed protocols reported by Zeiger et al.^46^ p-Toluenesulfonamide was sent to the testing laboratory (BioReliance Corporation, Rockville, MD) as a coded aliquot. It was incubated with the Salmonella typhimurium tester strains TA98, TA100, and TA102 either in buffer or S9 mix (metabolic activation enzymes and cofactors from Aroclor 1254-induced male Sprague-Dawley rat liver) for 20 minutes at 37°C. Top agar supplemented with L-histidine and d-biotin was added, and the contents of the tubes were mixed and poured onto the surfaces of minimal glucose agar plates. Histidine-independent mutant colonies arising on these plates were counted following incubation for 2 days at 37°C.

Each trial consisted of triplicate plates of concurrent positive and negative controls and of five doses of p-toluenesulfonamide. The highest noncytotoxic dose was 3,333 μg/plate.

In this assay, a positive response is defined as a reproducible, dose-related increase in histidine-independent (revertant) colonies in any one strain/activation combination. An equivocal response is defined as an increase in revertants that is not dose related, is not reproducible, or is not of sufficient magnitude to support a determination of mutagenicity. A negative response is obtained when no increase in revertant colonies is observed following chemical treatment. There is no minimum percentage or fold-increase required for a chemical to be judged positive or weakly positive, although positive calls are typically reserved for increases in mutant colonies that are at least twofold over background.

### Rat and Mouse Peripheral Blood Micronucleus Test Protocol

A detailed discussion of this assay is presented by Witt et al.^47^ and Torous et al.^48^ At the end of the 3-month studies, small peripheral blood samples (60 to 120 uL) were obtained from male and female F344/NTac rats and mice, placed in tubes containing EDTA, chilled, and shipped with cold packs by overnight courier to the testing laboratory (ILS, Inc., Research Triangle Park, NC) where they were immediately fixed in ultracold methanol [MicroFlow^®^ Basic Kits, Litron Laboratories, Rochester NY; Dertinger et al.^49^] and stored at −80°C until analysis. Flow cytometric analyses were conducted using a FACSCalibur flow cytometer (Becton Dickinson, San Jose, CA). Reticulocytes (RETs) were identified by the presence of an active transferrin receptor (CD71^+^) on the cell surface; mature erythrocytes were identified as CD71-negative (CD71^–^).

For F344/NTac rat blood samples, the analysis was restricted to the youngest RETs (i.e., the subpopulation of erythrocytes with the highest CD71 expression) to focus on the population of RETs that were least altered by the efficient action of the F344/NTac rat spleen in sequestering and destroying micronucleated red blood cells.^50^ Using flow cytometry, micronuclei were detected using the DNA staining dye propidium iodide (PI) in conjunction with RNase treatment. Therefore, micronucleated RETs express high levels of CD71 (CD71^+^) and PI-associated fluorescence, while micronucleated erythrocytes are negative for CD71 (CD71^−^) and show PI-associated fluorescence. Twenty thousand CD71^+^ RETs (polychromatic erythrocytes, PCEs) were scored per animal for presence of micronuclei, and approximately 1 million total erythrocytes (normochromatic erythrocytes, NCEs) were counted for the presence of micronuclei and to determine the percentage of RETs (% PCEs) as a measure of chemical-induced bone marrow toxicity.

Based on prior experience with the large number of cells scored using flow cytometric scoring techniques,^51^ it is reasonable to assume that the proportion of micronucleated RETs is approximately normally distributed. The statistical tests selected for trend and for pairwise comparisons with the control group depend on whether the variances among the groups are equal. Levene’s test at α = 0.05 is used to test for equal variances. In the case of equal variances, linear regression is used to test for a linear trend with dose and Williams’ test is used to test for pairwise differences between each treatment group and the control group. In the case of unequal variances, Jonckheere’s test is used to test for linear trend and Dunn’s test is used for pairwise comparisons of each treatment group with the control group. To correct for multiple pairwise comparisons, the P value for each comparison with the control group is multiplied by the number of comparisons made. In the event that this product is greater than 1.00, it is replaced with 1.00. Trend tests and pairwise comparisons with the controls are considered statistically significant at P ≤ 0.025, which is a Bonferroni correction to an overall 0.05 level of significance to adjust for testing for both trend and pairwise comparison. Ultimately, the scientific staff determines the final call after considering the results of statistical analyses, reproducibility of any effects observed, and the magnitudes of those effects.

### Evaluation Protocol

These are the basic guidelines for arriving at an overall assay result for assays performed by the National Toxicology Program. Statistical as well as biological factors are considered. For an individual assay, the statistical procedures for data analysis have been described in the preceding protocols. There have been instances, however, in which multiple samples of a chemical were tested in the same assay, and different results were obtained among these samples and/or among laboratories. Results from more than one aliquot or from more than one laboratory are not simply combined into an overall result. Rather, all the data are critically evaluated, particularly with regard to pertinent protocol variations, in determining the weight of evidence for an overall conclusion of chemical activity in an assay. In addition to multiple aliquots, the in vitro assays have another variable that must be considered in arriving at an overall test result. In vitro assays are conducted with and without exogenous metabolic activation. Results obtained in the absence of activation are not combined with results obtained in the presence of activation; each testing condition is evaluated separately. The results presented in the Abstract of this Toxicity Study Report represent a scientific judgment of the overall evidence for activity of the chemical in an assay.