# Introduction

Figure 1

p-Toluenesulfonamide (CASRN 70-55-3; Chemical Formula: C_7_H_9_NO_2_S; Molecular Weight: 171.23)

Synonyms: Benzenesulfonamide, 4-methyl-; 4-methylbenzenesulfonamide; p-methylbenzenesulfonamide; 4-methylphenylsulfonamide; plasticizer 15; p-toluenesulfamide; 4-toluenesulfanamide; toluene-4-sulfonamide; 4-toluenesulfonic acid, amide; p-toluenesulfonylamide; toluene-p-sulphonamide; tolylsulfonamide; p-tolylsulfonamide; tosylamide; p-tosylamide.

Trade Names: Uniplex 173, Halamid^®^ Aqua.

## Chemical and Physical Properties

p-Toluenesulfonamide is a nonvolatile chemical that exists in solid form as white flakes or crystalline powder and is stable in neutral, acidic, or alkaline conditions.^1^ It has a melting point of 138.5°C, boiling point of 214°C, molecular weight of 171.23, acid dissociation constant of 10.17 at 20°C, and octanol/water partition coefficient of 0.82 and is soluble in alcohol and water (3.16 × 10^3^ mg/L water at 25°C).^2^

## Production, Use, and Human Exposure

p-Toluenesulfonamide is used as a plasticizer, an intermediate for pesticides and drugs, and is the primary degradation product of the disinfectant chloramine-T.^3-5^ p-Toluenesulfonamide may be present as a contaminant in saccharin.^6^ Local injection of p-toluenesulfonamide is being studied as an investigational anticancer drug in China for lung cancer in combination with other drugs.^7^

The U.S. Fish and Wildlife Service reports that chloramine-T is being tested for use in aquaculture because of the chemical’s ability to kill bacterial colonies that form on fish in fish culture tanks.^8,9^ Although chloramine-T is not licensed in the United States for use as a disinfectant in the aquaculture industry for producing fish intended for human consumption, its use has been investigated under an investigational new animal drug^10^ as a treatment for bacterial gill disease in freshwater or marine aquaria, garden ponds, or other aquatic systems at concentrations ranging from 6.5 to 8.5 mg/L as a 1 hour flow-through treatment.^11^ Another study reports that up to four 60-minute exposures of between 10 and 20 mg chloramine-T/L administered once daily on consecutive or alternative days was effective in reducing fish mortality associated with bacterial infections.^12^ A mean concentration of p-toluenesulfonamide in fish after chloramine-T exposure at a concentration of 600 mg/L water was approximately 1,000 ng/g.^4^

Chloramine-T is used in Europe in aquaculture as a prevention treatment for bacterial disease using 10 mg/L in water in a flow-through basin for 1 hour^13^ and is also used in the food industry to disinfect equipment and machinery before processing. p-Toluenesulfonamide was found in ice cream at a range of 0.55 to 4.44 mg p-toluenesulfonamide/kg ice cream.^14^ In a study conducted in Germany, p-toluenesulfonamide was found in wastewater (<0.02 to 50.8 µg/L), in groundwater below a former sewage farm (<0.02 to 41 µg/L), in surface water (<0.02 to 1.15 µg/L), and in drinking water (<0.02 to 0.27 µg/L).^5^

Chloramine-T is listed as a main ingredient in whirlpool antiseptics,^15^ in various animal husbandry procedures as a disinfectant,^16^ and as a laboratory reagent to detect cyanide.^17^ p-Toluenesulfonamide is used as an intermediate for pesticide and drug production.^1^

Mean production volume for chloramine-T in the United States is reported as less than 500,000 pounds.^18^ The National Occupational Exposure Survey reported that between 4,000 and 9,000 workers may be exposed to chloramine-T annually at 200 to 300 facilities in the United States.^19^

The United States Environmental Protection Agency^20^ reports that p-toluenesulfonamide is not readily biodegradable in the environment.

## Regulatory Status

According to the German Federal Environmental Agency, the tolerable concentration limit of p-toluenesulfonamide in drinking water is 0.3 μg/L^3^. An Investigational New Animal Drug application has been submitted to the United States Food and Drug Administration for use of chloramine-T in public fish hatcheries.^4^

## Absorption, Distribution, Metabolism, Excretion, and Toxicokinetics

p-Toluenesulfonamide was well absorbed in female Wistar albino rats and excreted mainly in urine following oral administration of 29 or 200 mg/kg [^14^C] p-toluenesulfonamide.^6^ Twenty-four hours after dosing, urinary excretion (combined urine and cage rinse) accounted for approximately 90% and 77% and fecal excretion accounted for approximately 4% and 1% of the 29 and 200 mg/kg doses, respectively. More than 90% of the urinary radioactivity was associated with 4-sulphamoylbenzoic acid; other minor components included p-toluenesulfonamide, 4-sulphamoylbenzyl alcohol, 4-sulphamoylbenzaldehyde, and, at the higher dose, N-acetyltoluene-4-sulphonamide (Figure 2). In another study, following oral administration of 300 mg/kg [^35^S] p-toluenesulfonamide in Wistar rats, 80% of the administered dose was found in urine with 4-sulphamoylbenzoic acid accounting for 50% of the urinary radioactivity.^21^ Experiments in dogs suggested a similar metabolic pathway; 4-sulphamoylbenzoic acid was found in the urine of dogs given p-toluenesulfonamide.^22^ Following intravenous administration of 33 or 198 mg/kg p-toluenesulfonamide to male Wistar rats for 4 days, total cytochrome P450 content in control and treated animals was similar.^23^ The authors demonstrated that p-toluenesulfonamide metabolism is likely mediated through CYP2C7, CYP2D1, and CYP3A2.

Figure 2

Metabolism of p-Toluenesulfonamide

Chloramine-T has been studied in fish and rats. In male Wistar rats following oral administration of 100 mg/kg or intravenous administration of 30 mg/kg, chloramine-T was rapidly distributed and eliminated with distribution and elimination half-lives of 0.42 and 1.98 hours for oral and 0.12 and 1.41 hours for intravenous administration, respectively.^24^ In another study, following oral administration of 100 mg/kg or an intraperitoneal injection of 5 mg/kg for 4 consecutive days in Wistar rats, chloramine-T was rapidly absorbed and distributed to the brain (the only tissue measured in this study).^25^ Following exposure of adult rainbow trout to 20 mg [^14^C] chloramine-T, the major product detected in whole body homogenates was p-toluenesulfonamide; residual chloramine-T was not detected suggesting complete conversion of chloramine-T.^26^ When fingerlings or juvenile trout were exposed to 20 mg/L of [^14^C] chloramine-T for up to 1 hour and then transferred to fresh water for recovery, the half-lives of p-toluenesulfonamide estimated by radiometric analysis of whole body homogenates were 27.3 and 32.6 hours in fingerlings and juveniles, respectively.^26^

## Toxicity

### Experimental Animals

LD_50_ toxicity values reported for p-toluenesulfonamide are 2,330 mg/kg body weight (rat via oral gavage); 2,400 mg (mixture of 41% ortho- and 51% p-toluenesulfonamide)/kg (rat via oral gavage); 250 mg/kg (mouse via intraperitoneal injection); and 75 mg/kg (wild bird via oral gavage).^2,27^

No 14-day or 90-day rodent toxicity studies of p-toluenesulfonamide or chloramine-T were found in the peer-reviewed scientific literature. However, the USEPA reported that they had received toxicity study reports.

The USEPA^28^ reports that it has received the results of a 90-day p-toluenesulfonamide Organisation for Economic Co-operation and Development (OECD) 408 toxicity study in rats (species of rats not specified) conducted by industry. The p-toluenesulfonamide was administered in the diet at concentrations of 0, 1,000, 3,000, or 10,000 ppm (approximately 0, 70, 214, and 738 mg/kg per day for males and 0, 80, 248, 795 mg/kg per day for females). Administration of 10,000 ppm resulted in a 21% reduction in body weight. Hyperplasia of the urothelium of the urinary bladder occurred in two of 10 males at 10,000 ppm. No other major treatment-related effects were reported in the summary.

Survival for different strains of fish was measured at chloramine-T concentrations of 0, 20, 60, 100, or 200 mg/L. Decreased survival of fish occurred at chloramine-T exposures of 60 mg/L or greater 96 hours after a 60 or 180 minute exposure period.^12^ The recommended maximum chloramine-T concentration for use in aquaculture is 20 mg/L.^12^

The European Medicines Evaluation Agency^26^ reported on a study in rats (strain not specified) exposed to chloramine-T through feeding for either 28 days or 90 days. The target doses for the 28- and 90-day exposures ranged from 150 to 1,500 mg/kg (0.533 to 5.325 mmol/kg per day) and 5 to 150 mg/kg per day (18 to 533 μmol/kg per day), respectively. Reduced body weight gains were observed in treated animals. Relative kidney weights were increased in all dosed groups in the 28-day study and in the two highest dosed groups in the 90-day study. Relative liver weights were increased in all of the dosed groups in the 90-day study. Slight increases in leukocytes and pale, discolored livers were observed in the two highest dosed groups in the 28-day study. Increased severity and frequency of calcareous deposits occurred in the kidneys of female rats receiving 50 and 150 mg/kg per day (180 and 533 μmol/kg per day) in the 90-day study.

### Humans

Local injection of p-toluenesulfonamide was associated with mild fever, local pain, and somnolence that resolved spontaneously in a study conducted in China.^7^ Local p-toluenesulfonamide injection did not appear to potentiate toxicity of gemcitabine plus cisplatin chemotherapy.^7^

## Reproductive and Developmental Toxicity

### Experimental Animals

The USEPA High Production Volume Information System contains a summary of a one generation reproductive oral gavage p-toluenesulfonamide study sponsored by industry.^29^ In this study, Crj:CD(SD) male rats were exposed to p-toluenesulfonamide 42 days prior to mating and female rats were exposed for 14 days before mating through lactation day 3 at oral doses of 0, 120, 300, and 750 mg/kg. In the high-dose group, newborn rats showed significant decreases in body weight and survival rate. Mating performance and fertility were not affected by the test compound. Reproduction parameters were comparable among all four groups including the control. No remarkable histopathologic changes in the ovaries were observed in any of the non-pregnant females. Morphologic observations for offspring revealed no teratogenic effect of the test substance.^30^

No studies examining the potential for developmental or prenatal toxicity in animals were found in a search of the peer-reviewed scientific literature.

### Humans

No studies examining the potential for reproductive toxicity of p-toluenesulfonamide or chloramine-T in humans were found in a search of the peer-reviewed scientific literature.

## Carcinogenicity

No studies examining the potential for carcinogenic activity of p-toluenesulfonamide or chloramine-T in animals or epidemiology studies in humans were found in a search of the peer-reviewed scientific literature.

## Genetic Toxicity

Only one publication reporting results from genotoxicity tests with p-toluenesulfonamide was identified in a search of the peer-reviewed scientific literature. Eckhardt et al.^31^ tested p-toluenesulfonamide in assays for bacterial mutagenicity (using Salmonella typhimurium strains TA98, TA100, TA1535, TA1537, and TA1538), sex-linked recessive lethal mutation induction in male Drosophila melanogaster, and micronucleus induction in bone marrow reticulocytes of male and female NMRI mice. The authors reported a small but significant increase in mutant colonies in Salmonella strain TA98 in the presence of 10% rat liver S9 when testing was conducted using a nontraditional medium, ZLM, and doses of p-toluenesulfonamide (9,600 to 18,000 μg/plate) that far exceeded the limit doses that are currently used (5,000 to 6,000 μg/plate). In tests using the traditional Vogel-Bonner medium, no mutagenicity was observed at any dose level, with or without S9. In the sex-linked recessive lethal mutation assay, an increase in lethals (0.67%) was observed in brood 1 following 3 days of feeding the adult male flies on a sucrose solution containing 2.5 mM p-toluenesulfonamide. In the mouse micronucleus test, no increase in micronucleated reticulocytes was observed in bone marrow following administration of 855 mg p-toluenesulfonamide/kg body weight either by intraperitoneal injection or by gavage, although the protocol was not optimal for detecting micronucleated cells in the bone marrow.

Additional, publicly available (but not published) information was found in the USEPA High Production Volume Information System database^32^ where results from genotoxicity tests with p-toluenesulfonamide using bacterial mutagenicity assays and an in vitro chromosomal aberration test are reported. p-Toluenesulfonamide (doses up to 5,000 μg/plate) was not mutagenic in S. typhimurium strains TA98, TA100, TA1535, or TA1537, with or without S9 and no induction of chromosomal aberrations was seen in cultured Chinese hamster lung cells. The highest concentration used in the chromosomal aberrations test in the presence of S9 was 1.7 mg/mL and the highest concentration used in the absence of S9 was 1.3 mg/mL. p-Toluenesulfonamide was cytotoxic at a dose of 2.0 mg/mL in the absence of S9 and was cytotoxic at a concentration greater than 2.0 mg/mL in the presence of S9.

## Study Rationale

Chloramine-T was nominated by a private individual for toxicologic characterization due to its status as an investigational new animal drug for controlling proliferative gill disease and bacterial gill disease in aquaculture. In response to the nomination, the FDA requested using p-toluenesulfonamide as the study test article because it is the primary residue in chloramine-T treated fish intended for human consumption. In addition to p-toluenesulfonamide 3-month toxicity studies, NTP conducted bacterial mutagenicity tests using standardized protocols.