# Appendix G Feed and Compound Consumption in the Feed Studies of p-Toluenesulfonamide

Table G-1 Feed and Compound Consumption by F344/N Rats in the Two-week Feed Study of p-Toluenesulfonamide

Week | 0 ppm | | 750 ppm | | | 1,500 ppm | | | 3,000 ppm
Week | Feed^a^ (g/day) | Body Weight (g) | Feed (g/day) | Body Weight (g) | Dose^b^ (mg/kg) | Feed (g/day) | Body Weight (g) | Dose (mg/kg) | Feed (g/day) | Body Weight (g) | Dose (mg/kg)
Male
1 | – | 90 | – | 91 | – | – | 91 | – | – | 93 | –
2 | 15.5 | 127 | 16.4 | 126 | 98 | 14.6 | 124 | 177 | 15.6 | 128 | 366
3 | 16.5 | 161 | 14.2 | 153 | 70 | 16.1 | 161 | 150 | 15.6 | 159 | 295
Female
1 | – | 90 | – | 89 | – | – | 87 | – | – | 88 | –
2 | 12.2 | 108 | 11.9 | 110 | 81 | 12.1 | 108 | 168 | 11.7 | 103 | 340
3 | 10.5 | 126 | 11.9 | 128 | 70 | 11.8 | 125 | 142 | 11.6 | 121 | 288
| | | | | | 10,000 ppm | | | 30,000 ppm
| | | | | | Feed (g/day) | Body Weight (g) | Dose (mg/kg) | Feed (g/day) | Body Weight (g) | Dose (mg/kg)
Male
1 | | | | | | – | 91 | – | – | 89 | –
2 | | | | | | 12.9 | 116 | 1,110 | 8.3 | 92 | 2,698
3 | | | | | | 14.8 | 147 | 1,005 | 12.8 | 114 | 3,369
Female
1 | | | | | | – | 90 | – | – | 90 | –
2 | | | | | | 11.0 | 104 | 1,061 | 7.5 | 92 | 2,449
3 | | | | | | 10.8 | 118 | 913 | 9.6 | 104 | 2,761

^a^ Grams of feed consumed per animal per day.

^b^ Milligrams of p-toluenesulfonamide consumed per kilogram body weight per day.

Table G-2 Feed and Compound Consumption by Male F344/NTac Rats in the Three-month Feed Study of p-Toluenesulfonamide

Week | 0 ppm | | 625 ppm | | | 1,250 ppm | | | 2,500 ppm
Week | Feed^a^ (g/day) | Body Weight (g) | Feed (g/day) | Body Weight (g) | Dose^b^ (mg/kg) | Feed (g/day) | Body Weight (g) | Dose (mg/kg) | Feed (g/day) | Body Weight (g) | Dose (mg/kg)
1 | – | 87 | – | 87 | – | – | 89 | – | – | 89 | –
2 | 16.2 | 124 | 16.4 | 123 | 83 | 16.6 | 126 | 165 | 15.5 | 122 | 318
3 | 16.5 | 156 | 16.3 | 156 | 65 | 17.0 | 161 | 132 | 15.8 | 154 | 257
4 | 18.1 | 190 | 17.5 | 189 | 58 | 18.3 | 195 | 117 | 17.1 | 184 | 232
5 | 17.9 | 219 | 17.8 | 215 | 52 | 18.3 | 223 | 103 | 17.4 | 210 | 207
6 | 16.2 | 240 | 16.7 | 233 | 45 | 17.9 | 243 | 92 | 16.9 | 229 | 185
7 | 18.5 | 261 | 17.2 | 253 | 43 | 18.0 | 264 | 85 | 17.9 | 250 | 179
8 | 17.5 | 273 | 16.0 | 260 | 39 | 16.7 | 266 | 78 | 17.0 | 261 | 163
9 | 17.3 | 288 | 16.6 | 276 | 38 | 16.9 | 283 | 75 | 16.9 | 275 | 154
10 | 16.7 | 298 | 15.3 | 283 | 34 | 18.8 | 287 | 82 | 16.5 | 288 | 143
11 | 15.0 | 305 | 17.0 | 299 | 36 | 19.2 | 310 | 78 | 16.2 | 298 | 136
12 | 16.9 | 316 | 16.4 | 306 | 34 | 17.5 | 319 | 69 | 15.9 | 304 | 131
13 | 16.6 | 329 | 15.8 | 315 | 31 | 16.5 | 331 | 62 | 15.9 | 307 | 130
14 | 16.6 | 339 | 16.1 | 325 | 31 | 16.0 | 338 | 59 | 16.9 | 323 | 131
| | | | | | 5,000 ppm | | | 10,000 ppm
| | | | | | Feed (g/day) | Body Weight (g) | Dose (mg/kg) | Feed (g/day) | Body Weight (g) | Dose (mg/kg)
1 | | | | | | – | 87 | – | – | 87 | –
2 | | | | | | 14.1 | 115 | 615 | 13.2 | 112 | 1,182
3 | | | | | | 15.4 | 145 | 532 | 14.2 | 141 | 1,009
4 | | | | | | 16.7 | 175 | 478 | 15.5 | 168 | 922
5 | | | | | | 17.1 | 202 | 422 | 30.2 | 195 | 1,553
6 | | | | | | 17.2 | 223 | 386 | 16.6 | 213 | 780
7 | | | | | | 17.4 | 242 | 360 | 16.8 | 235 | 715
8 | | | | | | 17.8 | 252 | 353 | 15.9 | 246 | 646
9 | | | | | | 16.2 | 263 | 308 | 16.0 | 261 | 614
10 | | | | | | 13.3 | 269 | 247 | 16.0 | 274 | 584
11 | | | | | | 17.1 | 287 | 298 | 16.4 | 287 | 572
12 | | | | | | 16.5 | 295 | 279 | 15.8 | 293 | 540
13 | | | | | | 16.3 | 311 | 262 | 16.0 | 307 | 522
14 | | | | | | 16.7 | 320 | 261 | 15.9 | 315 | 505

^a^ Grams of feed consumed per animal per day.

^b^ Milligrams of p-toluenesulfonamide consumed per kilogram body weight per day.

Table G-3 Feed and Compound Consumption by Female F344/NTac Rats in the Three-month Feed Study of p-Toluenesulfonamide

Week | 0 ppm | | 625 ppm | | | 1,250 ppm | | | 2,500 ppm
Week | Feed^a^ (g/day) | Body Weight (g) | Feed (g/day) | Body Weight (g) | Dose^b^ (mg/kg) | Feed (g/day) | Body Weight (g) | Dose (mg/kg) | Feed (g/day) | Body Weight (g) | Dose (mg/kg)
1 | – | 83 | – | 86 | – | – | 85 | – | – | 84 | –
2 | 12.1 | 105 | 12.8 | 106 | 76 | 13.0 | 106 | 154 | 12.3 | 105 | 294
3 | 12.1 | 122 | 12.5 | 122 | 64 | 12.3 | 123 | 125 | 12.3 | 120 | 257
4 | 12.4 | 136 | 12.7 | 136 | 59 | 12.2 | 135 | 113 | 12.4 | 134 | 232
5 | 12.1 | 149 | 12.5 | 148 | 53 | 11.9 | 146 | 102 | 12.2 | 145 | 211
6 | 11.8 | 156 | 12.0 | 154 | 49 | 12.0 | 153 | 98 | 12.0 | 154 | 195
7 | 12.1 | 164 | 12.3 | 163 | 47 | 11.6 | 160 | 90 | 11.6 | 156 | 185
8 | 11.8 | 169 | 11.3 | 167 | 42 | 11.2 | 164 | 85 | 11.6 | 164 | 177
9 | 11.4 | 175 | 11.3 | 172 | 41 | 11.4 | 172 | 83 | 11.7 | 171 | 171
10 | 11.1 | 177 | 11.3 | 176 | 40 | 10.4 | 173 | 75 | 11.1 | 173 | 161
11 | 11.1 | 182 | 11.5 | 181 | 40 | 11.0 | 175 | 79 | 11.6 | 179 | 162
12 | 10.5 | 186 | 11.1 | 186 | 37 | 11.1 | 184 | 75 | 10.9 | 182 | 150
13 | 10.4 | 189 | 10.6 | 187 | 36 | 10.5 | 185 | 71 | 10.8 | 185 | 146
14 | 10.3 | 190 | 10.8 | 190 | 36 | 10.2 | 187 | 68 | 10.3 | 187 | 138
| | | | | | 5,000 ppm | | | 10,000 ppm
| | | | | | Feed (g/day) | Body Weight (g) | Dose (mg/kg) | Feed (g/day) | Body Weight (g) | Dose (mg/kg)
1 | | | | | | – | 86 | – | – | 85 | –
2 | | | | | | 11.6 | 105 | 555 | 10.6 | 99 | 1,071
3 | | | | | | 11.5 | 120 | 478 | 10.4 | 112 | 932
4 | | | | | | 12.0 | 133 | 451 | 11.1 | 125 | 890
5 | | | | | | 11.6 | 144 | 403 | 10.5 | 136 | 773
6 | | | | | | 11.6 | 151 | 384 | 11.2 | 143 | 783
7 | | | | | | 11.1 | 158 | 352 | 10.6 | 150 | 707
8 | | | | | | 10.8 | 161 | 336 | 10.5 | 153 | 687
9 | | | | | | 11.1 | 167 | 333 | 10.5 | 159 | 660
10 | | | | | | 10.6 | 169 | 313 | 9.7 | 161 | 604
11 | | | | | | 10.8 | 176 | 308 | 10.4 | 167 | 623
12 | | | | | | 10.4 | 178 | 292 | 9.8 | 170 | 577
13 | | | | | | 10.1 | 182 | 278 | 9.4 | 172 | 547
14 | | | | | | 10.1 | 184 | 275 | 9.6 | 174 | 550

^a^ Grams of feed consumed per animal per day.

^b^ Milligrams of p-toluenesulfonamide consumed per kilogram body weight per day.

Table G-4 Feed and Compound Consumption by Mice in the Two-week Feed Study of p-Toluenesulfonamide

Week | 0 ppm | | 750 ppm | | | 1,500 ppm | | | 3,000 ppm
Week | Feed^a^ (g/day) | Body Weight (g) | Feed (g/day) | Body Weight (g) | Dose^b^ (mg/kg) | Feed (g/day) | Body Weight (g) | Dose (mg/kg) | Feed (g/day) | Body Weight (g) | Dose (mg/kg)
Male
1 | – | 22.1 | – | 22.5 | – | – | 22.4 | – | – | 22.7 | –
2 | 5.1 | 23.3 | 5.0 | 23.4 | 160 | 4.1 | 23.4 | 263 | 5.8 | 23.0 | 756
3 | 4.6 | 24.6 | 4.4 | 24.7 | 134 | 5.2 | 23.9 | 326 | 5.3 | 24.8 | 641
Female
1 | – | 16.9 | – | 17.2 | – | – | 17.3 | – | – | 17.0 | –
2 | 3.5 | 18.2 | 3.0 | 17.9 | 125 | 3.3 | 17.6 | 281 | 4.0 | 17.8 | 673
3 | 3.9 | 19.6 | 3.1 | 19.3 | 120 | 3.4 | 18.5 | 276 | 3.6 | 19.0 | 567
| | | | | | 10,000 ppm | | | 30,000 ppm
| | | | | | Feed (g/day) | Body Weight (g) | Dose (mg/kg) | Feed (g/day) | Body Weight (g) | Dose (mg/kg)
Male
1 | | | | | | – | 22.3 | – | – | 22.1 | –
2 | | | | | | 4.7 | 22.9 | 2,054 | 5.2 | 20.6 | 7,573
3 | | | | | | 4.7 | 23.9 | 1,970 | 5.9 | 21.2 | 8,341
Female
1 | | | | | | – | 17.4 | – | – | 16.9 | –
2 | | | | | | 5.1 | 17.3 | 2,951 | 3.0 | 16.1 | 5,590
3 | | | | | | 3.7 | 19.1 | 1,941 | 3.7 | 16.6 | 6,679

^a^ Grams of feed consumed per animal per day.

^b^ Milligrams of p-toluenesulfonamide consumed per kilogram body weight per day.

Table G-5 Feed and Compound Consumption by Male Mice in the Three-month Feed Study of p-Toluenesulfonamide

Week | 0 ppm | | 625 ppm | | | 1,250 ppm | | | 2,500 ppm
Week | Feed^a^ (g/day) | Body Weight (g) | Feed (g/day) | Body Weight (g) | Dose^b^ (mg/kg) | Feed (g/day) | Body Weight (g) | Dose (mg/kg) | Feed (g/day) | Body Weight (g) | Dose (mg/kg)
1 | – | 22.2 | – | 22.2 | – | – | 22.7 | – | – | 22.7 | –
2 | 4.3 | 22.8 | 5.8 | 22.7 | 160 | 5.8 | 23.2 | 312 | 4.7 | 23.0 | 511
3 | 4.6 | 23.5 | 6.3 | 23.3 | 169 | 5.0 | 24.4 | 256 | 4.9 | 23.0 | 533
4 | 4.4 | 24.3 | 4.9 | 23.9 | 128 | 4.2 | 25.2 | 208 | 4.4 | 24.9 | 442
5 | 4.4 | 25.3 | 5.1 | 25.5 | 125 | 5.7 | 26.2 | 272 | 5.1 | 25.6 | 497
6 | 5.6 | 26.6 | 6.3 | 26.5 | 149 | 6.0 | 27.3 | 275 | 5.4 | 26.6 | 508
7 | 5.6 | 26.7 | 5.5 | 26.6 | 129 | 5.6 | 27.7 | 253 | 5.1 | 27.0 | 472
8 | 5.3 | 27.8 | 4.6 | 27.4 | 105 | 4.4 | 28.4 | 194 | 5.1 | 27.6 | 462
9 | 4.6 | 28.6 | 5.2 | 28.7 | 113 | 4.9 | 29.4 | 208 | 4.7 | 28.9 | 407
10 | 5.0 | 29.6 | 4.7 | 29.2 | 101 | 5.4 | 30.2 | 223 | 5.0 | 29.8 | 420
11 | 4.3 | 30.4 | 4.5 | 30.0 | 94 | 4.8 | 31.2 | 193 | 4.4 | 30.3 | 364
12 | 4.6 | 30.9 | 4.6 | 30.5 | 94 | 4.2 | 31.0 | 169 | 4.5 | 30.9 | 364
13 | 4.8 | 32.0 | 4.7 | 31.2 | 94 | 4.8 | 31.9 | 188 | 4.4 | 31.3 | 351
14 | 4.3 | 32.1 | 4.4 | 31.8 | 86 | 4.1 | 32.4 | 158 | 4.5 | 31.7 | 355
| | | | | | 5,000 ppm | | | 10,000 ppm
| | | | | | Feed (g/day) | Body Weight (g) | Dose (mg/kg) | Feed (g/day) | Body Weight (g) | Dose (mg/kg)
1 | | | | | | – | 22.7 | – | – | 22.4 | –
2 | | | | | | 4.1 | 23.0 | 893 | 4.8 | 22.4 | 2,144
3 | | | | | | 4.3 | 24.0 | 896 | 4.9 | 23.3 | 2,108
4 | | | | | | 4.1 | 24.7 | 831 | 4.2 | 24.2 | 1,734
5 | | | | | | 4.4 | 25.2 | 873 | 5.5 | 25.1 | 2,193
6 | | | | | | 7.5 | 26.1 | 1,437 | 6.4 | 26.0 | 2,458
7 | | | | | | 6.5 | 26.0 | 1,248 | 5.3 | 26.3 | 2,017
8 | | | | | | 5.3 | 26.3 | 1,006 | 5.2 | 26.8 | 1,940
9 | | | | | | 5.3 | 27.8 | 954 | 4.7 | 27.8 | 1,694
10 | | | | | | 5.9 | 28.9 | 1,022 | 4.9 | 28.2 | 1,737
11 | | | | | | 4.9 | 29.7 | 826 | 4.5 | 29.2 | 1,539
12 | | | | | | 4.7 | 30.2 | 779 | 4.1 | 29.1 | 1,409
13 | | | | | | 4.8 | 30.8 | 779 | 4.1 | 29.5 | 1,391
14 | | | | | | 4.1 | 30.8 | 666 | 4.4 | 30.0 | 1,466

^a^ Grams of feed consumed per animal per day.

^b^ Milligrams of p-toluenesulfonamide consumed per kilogram body weight per day.

Table G-6 Feed and Compound Consumption by Female Mice in the Three-month Feed Study of p-Toluenesulfonamide

Week | 0 ppm | | 625 ppm | | | 1,250 ppm | | | 2,500 ppm
Week | Feed^a^ (g/day) | Body Weight (g) | Feed (g/day) | Body Weight (g) | Dose^b^ (mg/kg) | Feed (g/day) | Body Weight (g) | Dose (mg/kg) | Feed (g/day) | Body Weight (g) | Dose (mg/kg)
1 | – | 18.4 | – | 18.7 | – | – | 18.7 | – | – | 18.7 | –
2 | 3.4 | 18.9 | 3.2 | 19.1 | 105 | 3.8 | 19.3 | 246 | 3.6 | 19.2 | 469
3 | 3.0 | 19.5 | 3.1 | 19.2 | 101 | 3.3 | 19.8 | 208 | 3.4 | 19.8 | 430
4 | 3.1 | 19.7 | 3.2 | 20.1 | 100 | 3.4 | 20.7 | 205 | 3.3 | 20.2 | 409
5 | 3.1 | 21.2 | 3.4 | 20.5 | 104 | 3.3 | 21.8 | 190 | 3.3 | 21.1 | 392
6 | 3.4 | 21.0 | 3.5 | 22.0 | 99 | 3.4 | 22.2 | 192 | 3.4 | 21.6 | 394
7 | 3.4 | 21.5 | 3.5 | 22.3 | 98 | 3.8 | 22.8 | 208 | 3.3 | 22.2 | 371
8 | 3.6 | 21.3 | 3.5 | 22.8 | 96 | 3.5 | 22.3 | 197 | 3.0 | 22.2 | 338
9 | 3.7 | 22.0 | 3.8 | 22.6 | 105 | 3.5 | 23.3 | 187 | 3.6 | 22.3 | 403
10 | 3.6 | 23.2 | 3.7 | 24.4 | 95 | 3.5 | 24.6 | 178 | 3.7 | 24.3 | 380
11 | 3.4 | 23.6 | 3.8 | 25.2 | 94 | 3.7 | 25.2 | 184 | 3.7 | 24.9 | 372
12 | 3.6 | 24.9 | 4.0 | 25.6 | 98 | 3.7 | 25.5 | 181 | 4.1 | 25.7 | 399
13 | 3.5 | 24.4 | 3.9 | 26.3 | 93 | 3.9 | 26.4 | 185 | 4.0 | 25.9 | 387
14 | 3.6 | 24.8 | 3.6 | 26.7 | 84 | 3.8 | 27.1 | 176 | 3.3 | 26.4 | 313
| | | | | | 5,000 ppm | | | 10,000 ppm
| | | | | | Feed (g/day) | Body Weight (g) | Dose (mg/kg) | Feed (g/day) | Body Weight (g) | Dose (mg/kg)
1 | | | | | | – | 18.8 | – | – | 18.5 | –
2 | | | | | | 3.4 | 19.2 | 885 | 3.6 | 19.0 | 1,898
3 | | | | | | 3.1 | 19.5 | 793 | 3.5 | 19.1 | 1,830
4 | | | | | | 3.4 | 20.1 | 846 | 4.2 | 20.0 | 2,100
5 | | | | | | 3.0 | 21.0 | 713 | 4.2 | 20.1 | 2,094
6 | | | | | | 3.3 | 21.7 | 762 | 4.1 | 21.4 | 1,920
7 | | | | | | 3.0 | 21.9 | 684 | 4.2 | 21.7 | 1,940
8 | | | | | | 3.9 | 23.0 | 848 | 5.0 | 22.6 | 2,215
9 | | | | | | 3.8 | 23.4 | 811 | 4.3 | 21.2 | 2,030
10 | | | | | | 3.6 | 23.2 | 777 | 4.4 | 22.9 | 1,924
11 | | | | | | 3.3 | 23.7 | 696 | 4.0 | 23.3 | 1,718
12 | | | | | | 3.6 | 24.8 | 727 | 4.6 | 23.9 | 1,921
13 | | | | | | 3.5 | 25.0 | 699 | 4.8 | 24.0 | 2,003
14 | | | | | | 3.5 | 25.4 | 689 | 4.6 | 24.8 | 1,857

^a^ Grams of feed consumed per animal per day.

^b^ Milligrams of p-toluenesulfonamide consumed per kilogram body weight per day.