# Appendix F Chemical Characterization and Dose Formulation Studies

## F.1 Procurement and Characterization of p-Toluenesulfonamide

p-Toluenesulfonamide was obtained from Acros Organics (Geel, Belgium) in one lot (A009615201). Lot A009615201 was purified by Battelle’s Organic Synthesis Group (Columbus, OH) and was renamed lot 112003. Lot 112003 was used in the 2-week and 3-month studies. Identity and purity analyses were conducted by the analytical chemistry laboratory at Battelle Columbus Operations (Columbus, OH). In addition, Karl Fischer titration and elemental analyses were performed by Prevalere Life Sciences, Inc. (Whitesboro, NY). Reports on analyses performed in support of the p-toluenesulfonamide studies are on file at the National Institute of Environmental Health Sciences.

Lot 112003 of the white crystalline chemical was identified as p-toluenesulfonamide using infrared (IR) and proton and carbon-13 nuclear magnetic resonance (NMR) spectroscopy and by melting point analysis. All spectra were consistent with computer calculated and/or literature spectra^57-59^ and the structure of p-toluenesulfonamide. Representative IR and proton NMR spectra are presented in Figure F-1 and Figure F-2. The melting point of the test chemical was determined to be 137.2°C, which is consistent with the literature value.

The moisture content of lot 112003 was determined using Karl Fischer titration. The purity of the bulk chemical was determined by elemental analyses, differential scanning calorimetry (DSC), and high-performance liquid chromatography (HPLC) with ultraviolet (UV) detection by system A (Table F-1). Tentative impurity identification was obtained using mass spectrometry (MS) detection by system B and proton and carbon-13 NMR spectroscopy. DSC was conducted using a Perkin-Elmer DSC-7 scanning calorimeter (Perkin Elmer, Waltham, MA), scanning from 100°C to 150°C for the first replicate and from 120°C to 150°C for the second and third replicates, at a scanning rate of 1°C per minute under a nitrogen atmosphere.

Karl Fischer titration indicated approximately 0.1% water. Elemental analyses for carbon, hydrogen, and nitrogen were in agreement with the theoretical values for p-toluenesulfonamide. DSC indicated a purity of 100%. HPLC/UV indicated one major peak and one reportable impurity with an individual area equal to 0.2% of the total peak area. The most probable structure for the impurity based on MS and NMR analyses was 4-methyl-N-phenylbenzene sulfonamide, although the impurity peak in the HPLC/UV analyses might have been composed of multiple components. The overall purity of lot 112003 was determined to be greater than 99%.

To ensure stability, the bulk chemical was stored under a headspace of inert gas at room temperature and protected from light in sealed amber glass bottles. Periodic reanalyses of the bulk chemical were performed at the study laboratory at BioReliance Corporation (Rockville, MD) during the 2-week and 3-month studies using HPLC/UV by system A, and no degradation of the bulk chemical was detected.

## F.2 Preparation and Analysis of Dose Formulations

The dose formulations were prepared once during the 2-week studies and eight times during the 3-month studies by mixing p-toluenesulfonamide with feed (Table F-2). A premix was prepared by hand and then blended with additional feed in a Patterson-Kelly twin-shell blender. Formulations were stored in doubled polyethylene bags sealed with twist ties protected from light at room temperature for up to 42 days.

Homogeneity studies of the 750 and 30,000 ppm dose formulations and stability studies of the 750 ppm dose formulation were performed by the analytical chemistry laboratory using HPLC/UV by system C (Table F-1). An additional homogeneity study of the 625 ppm dose formulation was performed by the study laboratory using HPLC/UV by system A. Homogeneity was confirmed, and stability was confirmed for at least 42 days for dose formulations stored in plastic zip-lock bags, protected from light, at temperatures up to room temperature, and for at least 7 days for dose formulations kept in glass feeding containers without urine and feces under simulated animal room conditions.

Periodic analyses of the dose formulations of p-toluenesulfonamide were conducted by the study laboratory using HPLC/UV by system A. During the 2-week studies, the dose formulations were analyzed once; all 10 dose formulations for rats and mice were within 10% of the target concentrations (Table F-3). Animal room samples of these dose formulations were also analyzed; all 10 for male rats and two of 10 for female mice were within 10% of the target concentrations. During the 3-month studies, the dose formulations were analyzed three times; animal room samples of these dose formulations were also analyzed (Table F-4). Of the dose formulations analyzed, all 34 for rats and mice were within 10% of the target concentrations; 15 of 30 animal room samples for rats and 13 of 30 for mice were within 10% of the target concentrations. Low recovery of p-toluenesulfonamide in many of the animal room samples was attributed to potential contamination of dosed-feed with urine and/or feces, which may have caused irreversible binding of the test chemical to the feed. A similar behavior was observed in the simulated animal room stability studies conducted on the 750 ppm dose formulation by the analytical chemistry laboratory where a decline of formulation concentration was observed in the presence of urine and feces.

Table F-1 High-Performance Liquid Chromatography Systems Used in the Feed Studies of p-Toluenesulfonamide^a^

Detection System | Column | Solvent System
System A
Ultraviolet (254 nm) light | Prodigy^TM^ ODS-3, 150 mm × 4.6 mm, 3 μm (Phenomenex, Torrance, CA) | A) 0.1% trifluoroacetic acid: 10% acetonitrile:90% water and B) 0.08% trifluoroacetic acid in acetonitrile; 100% A for 2 minutes, then linear gradient to 100% B in 13 minutes, held for 5 minutes, then linear gradient to 100% A in 0.1 minute, held for 9.9 minutes; flow rate 1.0 mL/minute
System B
Mass spectrometry with direct infusion | Not applicable | A) 50 mM ammonium acetate:0.1% acetic acid and B) methanol; 50% A:50% B, isocratic; flow rate 0.1 mL/minute
System C
Ultraviolet (254 nm) light | ProdigyTM ODS-3, 150 mm × 4.6 mm, 3 μm (Phenomenex) | A) 0.1% trifluoroacetic acid: 10% acetonitrile:90% water and B) 0.1% trifluoracetic acid: 90% acetonitrile:10% water; linear gradient from 100% A to 100% B in 15 minutes, held for 5 minutes, then linear gradient to 100% A in 0.1 minute, held for 9.9 minutes.

^a^ The high-performance liquid chromatographs were manufactured by Waters (Milford, MA) or Agilent (Palo Alto, CA). The mass spectrometer was manufactured by Micromass UK Limited (Manchester, England).

Table F-2 Preparation and Storage of Dose Formulations in the Feed Studies of p-Toluenesulfonamide

Two-week Studies | Three-month Studies
Preparation
A premix of feed and the appropriate amount of p-toluenesulfonamide, previously ground into a fine powder with a mortar and pestle and sieved through a number 14 sieve until no chemical agglomerates remained, was placed in a mortar with portions of clean feed, and ground manually with a pestle. The premix was then layered into the remaining clean feed and blended in a Patterson-Kelly twin-shell blender with the intensifier bar on for 5 minutes and off for 10 minutes. The dose formulations were prepared once during the studies. | A premix of feed and the appropriate amount of p-toluenesulfonamide, previously ground into a fine powder with a mortar and pestle, was layered into portions of clean feed, placed in a mortar and ground manually with a pestle and sieved through a number 14 sieve until no chemical/feed agglomerates remained. The premix was then layered into the remaining clean feed and blended in a Patterson-Kelly twin-shell blender with the intensifier bar on for 5 minutes and off for 10 minutes. The dose formulations were prepared eight times during the studies.
Chemical Lot Number
112003 | 112003
Maximum Storage Time
42 days | 42 days
Storage Conditions
Stored in doubled polyethylene bags sealed with twist ties protected from light at room temperature | Stored in doubled polyethylene bags sealed with twist ties protected from light at room temperature
Study Laboratory
BioReliance Corporation (Rockville, MD) | BioReliance Corporation (Rockville, MD)

Table F-3 Results of Analyses of Dose Formulations Administered to F344/N Rats and Mice in the Two-week Feed Studies of p-Toluenesulfonamide

Date Prepared | Date Analyzed | Target Concentration (ppm) | Determined Concentration^a^ (ppm) | Difference from Target (%)
June 27, 2006 | June 27–28, 2006 | 750 | 753 | 0
| | 750 | 752 | 0
| | 1,500 | 1,490 | −1
| | 1,500 | 1,480 | −1
| | 3,000 | 3,001 | 0
| | 3,000 | 3,001 | 0
| | 10,000 | 10,160 | +2
| | 10,000 | 9,829 | −2
| | 30,000 | 31,080 | +4
| | 30,000 | 31,160 | +4
| July 20–22, 2006^b^ | 750 | 675 | −10
| | 750 | 730 | −3
| | 1,500 | 1,454 | −3
| | 1,500 | 1,476 | −2
| | 3,000 | 2,885 | −4
| | 3,000 | 2,896 | −3
| | 10,000 | 9,270 | −7
| | 10,000 | 9,433 | −6
| | 30,000 | 30,810 | +3
| | 30,000 | 30,930 | +3
| July 20–22, 2006^c^ | 750 | 543 | −28
| | 750 | 561 | −25
| | 1,500 | 963 | −36
| | 1,500 | 933 | −38
| | 3,000 | 2,342 | −22
| | 3,000 | 2,296 | −23
| | 10,000 | 7,860^d^ | −21
| | 10,000 | 8,550^d^ | −15
| | 30,000 | 30,320 | +1
| | 30,000 | 28,660 | −4

^a^ Results of duplicate analyses.

^b^ Animal room samples for male rats.

^c^ Animal room samples for female mice.

^d^ Data taken from Table 16 of the BioReliance Dose Formulation and Purity Analysis Report dated 02/26/07.

Table F-4 Results of Analyses of Dose Formulations Administered to F344/NTac Rats and Mice in the Three-month Feed Studies of p-Toluenesulfonamide

Date Prepared | Date Analyzed | Target Concentration (ppm) | Determined Concentration^a^ (ppm) | Difference from Target (%)
October 5, 2006 | October 8 or 10, 2006 | 625 | 621^b^ | −1
| | 625 | 570^b^ | −9
| | 625 | 649^c^ | +4
| | 625 | 667^c^ | +7
| | 625 | 656^d^ | +5
| | 625 | 659^d^ | +5
| | 1,250 | 1,216 | −3
| | 1,250 | 1,187 | −5
| | 2,500 | 2,468 | −1
| | 2,500 | 2,494 | 0
| | 5,000 | 4,884 | −2
| | 5,000 | 4,814 | −4
| | 10,000 | 9,710 | −3
| | 10,000 | 9,747 | −3
| October 31, 2006^e^ | 625 | 525 | −16
| | 625 | 550 | −12
| | 1,250 | 954 | −24
| | 1,250 | 1,026 | −18
| | 2,500 | 2,019 | −19
| | 2,500 | 2,129 | −15
| | 5,000 | 3,968 | −21
| | 5,000 | 4,140 | −17
| | 10,000 | 8,225 | −18
| | 10,000 | 8,460 | −15
| October 31, 2006^f^ | 625 | 302 | −52
| | 625 | 288 | −54
| | 1,250 | 759 | −39
| | 1,250 | 850 | −32
| | 2,500 | 1,562 | −38
| | 2,500 | 1,554 | −38
| | 5,000 | 2,793 | −44
| | 5,000 | 2,835 | −43
| | 10,000 | 7,362 | −26
| | 10,000 | 7,338 | −27
November 27, 2006 | November 27, 2006 | 625 | 611 | −2
| | 625 | 572 | −8
| | 1,250 | 1,211 | −3
| | 1,250 | 1,279 | +2
| | 2,500 | 2,705 | +8
| | 2,500 | 2,736 | +9
| | 5,000 | 5,383 | +8
| | 5,000 | 5,070 | +1
| | 10,000 | 10,700 | +7
| | 10,000 | 10,620 | +6
| December 18, 2006^e^ | 625 | 502 | −20
| | 625 | 548 | −12
| | 1,250 | 1,123 | −10
| | 1,250 | 1,148 | −8
| | 2,500 | 2,371 | −5
| | 2,500 | 2,249 | −10
| | 5,000 | 4,919 | −2
| | 5,000 | 4,749 | −5
| | 10,000 | 9,502 | −5
| | 10,000 | 9,745 | −3
| December 18, 2006^f^ | 625 | 585 | −6
| | 625 | 594 | −5
| | 1,250 | 1,260 | +1
| | 1,250 | 1,194 | −4
| | 2,500 | 2,545 | +2
| | 2,500 | 2,369 | −5
| | 5,000 | 4,535 | −9
| | 5,000 | 4,843 | −3
| | 10,000 | 9,787 | −2
| | 10,000 | 9,833 | −2
December 19, 2006 | December 19, 2006 | 625 | 619 | −1
| | 625 | 617 | −1
| | 1,250 | 1,212 | −3
| | 1,250 | 1,227 | −2
| | 2,500 | 2,401 | −4
| | 2,500 | 2,397 | −4
| | 5,000 | 4,812 | −4
| | 5,000 | 4,998 | 0
| | 10,000 | 9,739 | −3
| | 10,000 | 9,839 | −2
| March 2, 2007^e^ | 625 | 586 | −6
| | 625 | 528 | −16
| | 1,250 | 1,012 | −19
| | 1,250 | 1,006 | −20
| | 2,500 | 2,373 | −5
| | 2,500 | 2,326 | −7
| | 5,000 | 4,733 | −5
| | 5,000 | 4,550 | −9
| | 10,000 | 9,356 | −6
| | 10,000 | 9,272 | −7
| March 2, 2007^f^ | 625 | 574 | −8
| | 625 | 522 | −16
| | 1,250 | 1,145 | −8
| | 1,250 | 1,105 | −12
| | 2,500 | 2,177 | −13
| | 2,500 | 2,136 | −15
| | 5,000 | 4,728 | −5
| | 5,000 | 4,402 | −12
| | 10,000 | 8,676 | −13
| | 10,000 | 8,723 | −13

^a^ Results of duplicate analyses.

^b^ Left blender position.

^c^ Right blender position.

^d^ Bottom blender position.

^e^ Animal room samples for rats.

^f^ Animal room samples for mice.

Figure F-1

Infrared Absorption Spectrum of p-Toluenesulfonamide

Figure F-2

Proton Nuclear Magnetic Resonance Spectrum of p-Toluenesulfonamide