# Appendix E Genetic Toxicology

Table E-1 Mutagenicity of p-Toluenesulfonamide in Salmonella typhimurium^a^

Strain | Dose (μg/plate) | Without S9 | With 10% rat S9
TA102
| 0 | 361 ± 25 | 408 ± 9
| 100 | 396 ± 9 | 359 ± 6
| 333 | 366 ± 33 | 414 ± 36
| 1,000 | 353 ± 8 | 374 ± 7
| 3,333 | 180 ± 21^c^ | 313 ± 14^c^
| 10,000 | 0 ± 0^c^ | 0 ± 0^c^
Trial summary | | Negative | Negative
Positive control^b^ | | 1,410 ± 34 | 1,423 ± 88
TA100
| 0 | 121 ± 5 | 125 ± 2
| 33 | 134 ± 9 | 139 ± 6
| 100 | 122 ± 9 | 138 ± 9
| 333 | 133 ± 10 | 136 ± 8
| 1,000 | 114 ± 5 | 145 ± 8
| 2,000 | 121 ± 6
| 3,333 | | 141 ± 2
Trial summary | | Negative | Negative
Positive control | | 595 ± 1 | 876 ± 65
TA98
| 0 | 17 ± 1 | 31 ± 1
| 33 | 15 ± 2 | 35 ± 2
| 100 | 20 ± 2 | 30 ± 2
| 333 | 15 ± 1 | 27 ± 10
| 1,000 | 17 ± 2 | 31 ± 2
| 2,000 | 19 ± 3
| 3,333 | | 0 ± 0^c^
Trial summary | | Negative | Negative
Positive control | | 80 ± 10 | 501 ± 28

^a^ Study was performed at BioReliance Corporation. Data are presented as revertants/plate (mean ± standard error) from three plates. The detailed protocol is presented by Zeiger et al.^46^ 0 μg/plate was the solvent control.

^b^ The positive controls in the absence of metabolic activation were sodium azide (TA100), 4-nitro-o-phenylenediamine (TA98), and mitomycin-C (TA102). The positive control for metabolic activation with all strains was 2-aminoanthracene, except 2-aminoanthracene or sterigmatocystin was used for TA102.

^c^ Slight toxicity.

Table E-2 Frequency of Micronuclei in Peripheral Blood Erythrocytes of F344/NTac Rats Following Administration of p-Toluenesulfonamide in Feed for Three Months^a^

Concentration (ppm) | Number of Rats with Erythrocytes Scored | Micronucleated PCEs/1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs^b^(%) | P Value^c^
Male
0 | 5 | 0.37 ± 0.07 | | 0.12 ± 0.04 | | 1.411 ± 0.07
625 | 5 | 0.47 ± 0.11 | 0.4098 | 0.16 ± 0.03 | 0.2146 | 1.336 ± 0.13 | 1.000
1,250 | 5 | 0.57 ± 0.07 | 0.4823 | 0.29 ± 0.04 | 0.2575 | 1.504 ± 0.04 | 0.852
2,500 | 5 | 0.36 ± 0.05 | 0.5133 | 0.14 ± 0.02 | 0.2759 | 1.416 ± 0.11 | 0.894
5,000 | 5 | 0.31 ± 0.05 | 0.5314 | 0.08 ± 0.03 | 0.2848 | 1.686 ± 0.11 | 0.090
10,000 | 5 | 0.27 ± 0.09 | 0.5419 | 0.10 ± 0.01 | 0.2920 | 1.676 ± 0.08 | 0.091
| | P = 0.980^d^ | | P = 0.975 | | P = 0.010
Female
0 | 5 | 0.46 ± 0.09 | | 0.20 ± 0.04 | | 1.062 ± 0.05
625 | 5 | 0.35 ± 0.07 | 0.7779 | 0.15 ± 0.02 | 0.6905 | 1.148 ± 0.07 | 0.469
1,250 | 5 | 0.32 ± 0.03 | 0.8551 | 0.20 ± 0.03 | 0.7758 | 1.288 ± 0.11 | 0.130
2,500 | 5 | 0.33 ± 0.08 | 0.8820 | 0.14 ± 0.03 | 0.8085 | 1.290 ± 0.10 | 0.139
5,000 | 5 | 0.43 ± 0.08 | 0.7365 | 0.20 ± 0.02 | 0.7287 | 1.223 ± 0.06 | 0.142
10,000 | 5 | 0.50 ± 0.14 | 0.4994 | 0.18 ± 0.08 | 0.7426 | 1.284 ± 0.13 | 0.139
| | P = 0.112 | | P = 0.450 | | P = 0.251

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Witt et al.^47^ and Torous et al.^48^ NCE = normochromatic erythrocyte; PCE = polychromatic erythrocyte.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the control group; exposed group values are significant at P ≤ 0.025 by Williams’ test.

^d^ Dose-related trend; significant at P ≤ 0.025 by linear regression.

Table E-3 Frequency of Micronuclei in Peripheral Blood Erythrocytes of Mice Following Administration of p-Toluenesulfonamide in Feed for Three Months^a^

Concentration (ppm) | Number of Mice with Erythrocytes Scored | Micronucleated PCEs/1,000 PCEs^b^ | P Value^c^ | Micronucleated NCEs/1,000 NCEs^b^ | P Value^c^ | PCEs^b^ (%) | P Value^d^
Male
0 | 5 | 2.64 ± 0.18 | | 1.47 ± 0.03 | | 1.538 ± 0.05
625 | 5 | 2.48 ± 0.21 | 0.6100 | 1.49 ± 0.03 | 0.3650 | 1.663 ± 0.04 | 0.136
1,250 | 5 | 2.84 ± 0.25 | 0.3212 | 1.50 ± 0.05 | 0.3605 | 1.647 ± 0.06 | 0.162
2,500 | 5 | 2.80 ± 0.14 | 0.3437 | 1.51 ± 0.02 | 0.3649 | 1.725 ± 0.04 | 0.038
5,000 | 5 | 2.87 ± 0.22 | 0.2989 | 1.51 ± 0.03 | 0.3782 | 1.710 ± 0.08 | 0.038
10,000 | 5 | 2.85 ± 0.21 | 0.3070 | 1.48 ± 0.02 | 0.3887 | 1.759 ± 0.05 | 0.011
| | P = 0.150^e^ | | P = 0.526^e^ | | P = 0.026^e^
Female
0 | 5 | 1.85 ± 0.13 | | 1.02 ± 0.03 | | 1.351 ± 0.16
625 | 5 | 1.77 ± 0.09 | 0.5748 | 1.03 ± 0.03 | 0.6186 | 1.289 ± 0.03 | 1.000
1,250 | 5 | 2.20 ± 0.18 | 0.3624 | 1.01 ± 0.02 | 0.7057 | 1.141 ± 0.12 | 1.000
2,500 | 5 | 1.82 ± 0.17 | 0.3865 | 1.01 ± 0.02 | 0.7404 | 1.471 ± 0.18 | 1.000
5,000 | 5 | 1.97 ± 0.08 | 0.4012 | 0.97 ± 0.02 | 0.7571 | 1.543 ± 0.06 | 1.000
10,000 | 5 | 1.86 ± 0.21 | 0.4121 | 0.98 ± 0.04 | 0.7704 | 1.525 ± 0.06 | 1.000
| | P = 0.555^e^ | | P = 0.927^e^ | | P = 0.085^f^

^a^ Study was performed at ILS, Inc. The detailed protocol is presented by Witt et al.^47^ and Torous et al.^48^ NCE = normochromatic erythrocyte; PCE = polychromatic erythrocyte.

^b^ Mean ± standard error.

^c^ Pairwise comparison with the control group; exposed group values are significant at P ≤ 0.025 by Williams’ test.

^d^ Pairwise comparison with the control group; exposed group values are significant at P ≤ 0.025 by Williams’ (males) or Dunn’s (females) test.

^e^ Dose-related trend; significant at P ≤ 0.025 by linear regression.

^f^ Dose-related trend; significant at P ≤ 0.025 by Jonckheere’s test.