# Appendix D Reproductive Tissue Evaluations in Male Rats and Mice

Table D-1 Summary of Reproductive Tissue Evaluations for Male F344/NTac Rats in the Three-month Feed Study of p-Toluenesulfonamide^a^

| 0 ppm | 2,500 ppm | 5,000 ppm | 10,000 ppm
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy body wt | 339 ± 7 | 323 ± 7 | 320 ± 6 | 314 ± 8*
L. Cauda epididymis | 0.1652 ± 0.0033 | 0.1716 ± 0.0039 | 0.1806 ± 0.0070 | 0.1754 ± 0.0054
L. Epididymis | 0.4439 ± 0.0115 | 0.4401 ± 0.0110 | 0.4504 ± 0.0093 | 0.4437 ± 0.0100
L. Testis | 1.5009 ± 0.0202 | 1.4818 ± 0.0291 | 1.4874 ± 0.0219 | 1.4634 ± 0.0278
Spermatid measurements
Spermatid heads (10^6^/g testis) | 149.97 ± 11.34 | 96.99 ± 7.74** | 110.66 ± 8.32 | 116.44 ± 7.10
Spermatid heads (10^6^/testis) | 225.87 ± 18.82 | 143.84 ± 12.03** | 164.39 ± 12.33 | 169.60 ± 9.41
Epididymal spermatozoal measurements
Sperm motility (%) | 66.1 ± 7.1 | 78.8 ± 6.0 | 83.6 ± 2.9 | 78.8 ± 5.2
Sperm (10^6^/g cauda epididymis) | 456.3 ± 34.0 | 478.1 ± 31.7 | 454.8 ± 32.3 | 454.3 ± 26.1
Sperm (10^6^/cauda epididymis) | 75.5 ± 6.0 | 81.3 ± 4.2 | 81.8 ± 6.1 | 79.7 ± 5.3

* Significantly different (P ≤ 0.05) from the control group by Dunnett’s test.

** Significantly different (P ≤ 0.01) from the control group by Dunn’s test.

^a^ Data are presented as mean ± standard error. Differences from the control group are not significant by Dunnett’s test (tissue weights) or Dunn’s test (epididymal spermatozoal measurements).

Table D-2 Summary of Reproductive Tissue Evaluations for Male Mice in the Three-month Feed Study of p-Toluenesulfonamide^a^

| 0 ppm | 2,500 ppm | 5,000 ppm | 10,000 ppm
n | 10 | 10 | 10 | 10
Weights (g)
Necropsy body wt | 32.1 ± 0.7 | 31.7 ± 0.9 | 30.8 ± 0.8 | 30.0 ± 0.7
L. Cauda epididymis | 0.0174 ± 0.0014 | 0.0217 ± 0.0036 | 0.0207 ± 0.0019 | 0.0189 ± 0.0013
L. Epididymis | 0.0479 ± 0.0045 | 0.0511 ± 0.0056 | 0.0504 ± 0.0035 | 0.0487 ± 0.0039
L. Testis | 0.1083 ± 0.0021 | 0.1163 ± 0.0024 | 0.1159 ± 0.0029 | 0.1181 ± 0.0048
Spermatid measurements
Spermatid heads (10^6^/g testis) | 207.94 ± 18.01 | 205.76 ± 10.65 | 216.08 ± 11.95 | 243.01 ± 19.94
Spermatid heads (10^6^/testis) | 22.35 ± 1.78 | 23.93 ± 1.34 | 25.04 ± 1.49 | 28.20 ± 2.00
Epididymal spermatozoal measurements
Sperm motility (%) | 95.4 ± 0.9 | 95.6 ± 0.8 | 93.5 ± 1.4 | 89.0 ± 3.9
Sperm (10^6^/g cauda epididymis) | 188.3 ± 13.1 | 146.6 ± 16.1 | 157.0 ± 14.8 | 190.8 ± 11.9
Sperm (10^6^/cauda epididymis) | 3.2 ± 0.2 | 2.8 ± 0.1 | 3.0 ± 0.2 | 3.5 ± 0.2

^a^ Data are presented as mean ± standard error. Differences from the control group are not significant by Dunnett’s test (body and tissue weights) or Dunn’s test (spermatid and epididymal spermatozoal measurements).