# Appendix C Organ Weights and Organ-Weight-to-Body-Weight Ratios

Table C-1 Organ Weights and Organ-Weight-to-Body-Weight Ratios for F344/N Rats in the Two-week Feed Study of p-Toluenesulfonamide^a^

| 0 ppm | 750 ppm | 1,500 ppm | 3,000 ppm | 10,000 ppm | 30,000 ppm
n | 5 | 5 | 5 | 5 | 5 | 5
Male
Necropsy body wt | 161 ± 5 | 153 ± 6 | 161 ± 4 | 159 ± 5 | 147 ± 3* | 114 ± 2**
Heart
Absolute | 0.61 ± 0.03 | 0.58 ± 0.03 | 0.64 ± 0.02 | 0.60 ± 0.03 | 0.56 ± 0.02 | 0.42 ± 0.01**
Relative | 3.77 ± 0.15 | 3.75 ± 0.11 | 3.96 ± 0.10 | 3.79 ± 0.09 | 3.82 ± 0.08 | 3.72 ± 0.05
R. Kidney
Absolute | 0.68 ± 0.03 | 0.67 ± 0.02 | 0.70 ± 0.01 | 0.71 ± 0.03 | 0.71 ± 0.02 | 0.55 ± 0.01**
Relative | 4.20 ± 0.11 | 4.35 ± 0.03 | 4.35 ± 0.06 | 4.44 ± 0.06* | 4.82 ± 0.03** | 4.82 ± 0.07**
Liver
Absolute | 8.17 ± 0.31 | 7.36 ± 0.35 | 8.06 ± 0.33 | 8.08 ± 0.39 | 7.62 ± 0.31 | 5.91 ± 0.10**
Relative | 50.55 ± 0.65 | 48.00 ± 0.88 | 50.10 ± 0.94 | 50.86 ± 0.98 | 51.70 ± 1.20 | 51.90 ± 0.83
Lung
Absolute | 0.97 ± 0.04 | 0.90 ± 0.05 | 0.85 ± 0.02* | 0.88 ± 0.05* | 0.83 ± 0.01* | 0.68 ± 0.01**
Relative | 6.01 ± 0.28 | 5.87 ± 0.24 | 5.28 ± 0.22* | 5.51 ± 0.12 | 5.66 ± 0.05 | 5.95 ± 0.10
R. Testis
Absolute | 0.845 ± 0.043 | 0.911 ± 0.041 | 0.907 ± 0.017 | 0.943 ± 0.035 | 0.862 ± 0.055 | 0.795 ± 0.050
Relative | 5.232 ± 0.192 | 5.942 ± 0.137 | 5.659 ± 0.174 | 5.952 ± 0.196 | 5.836 ± 0.285 | 6.960 ± 0.365**
Thymus
Absolute | 0.436 ± 0.019 | 0.355 ± 0.025 | 0.372 ± 0.030 | 0.395 ± 0.025 | 0.395 ± 0.029 | 0.253 ± 0.006**
Relative | 2.701 ± 0.100 | 2.316 ± 0.115 | 2.312 ± 0.172 | 2.479 ± 0.082 | 2.695 ± 0.239 | 2.220 ± 0.035
Female
Necropsy body wt | 126 ± 3 | 128 ± 2 | 125 ± 4 | 121 ± 2 | 118 ± 3 | 104 ± 1**
Heart
Absolute | 0.48 ± 0.01 | 0.49 ± 0.01 | 0.50 ± 0.02 | 0.46 ± 0.01 | 0.46 ± 0.01 | 0.42 ± 0.01**
Relative | 3.83 ± 0.07 | 3.87 ± 0.07 | 4.02 ± 0.08 | 3.81 ± 0.09 | 3.91 ± 0.08 | 3.99 ± 0.09
R. Kidney
Absolute | 0.56 ± 0.02 | 0.58 ± 0.01 | 0.57 ± 0.02 | 0.55 ± 0.01 | 0.56 ± 0.01 | 0.51 ± 0.00
Relative | 4.44 ± 0.11 | 4.52 ± 0.05 | 4.53 ± 0.07 | 4.58 ± 0.09 | 4.76 ± 0.08** | 4.90 ± 0.03**
Liver
Absolute | 5.47 ± 0.24 | 5.63 ± 0.15 | 5.52 ± 0.22 | 5.38 ± 0.09 | 5.37 ± 0.26 | 4.82 ± 0.09*
Relative | 43.49 ± 1.05 | 44.09 ± 0.97 | 44.07 ± 0.76 | 44.65 ± 1.14 | 45.29 ± 1.18 | 46.19 ± 0.82
Lung
Absolute | 0.72 ± 0.03 | 0.74 ± 0.02 | 0.74 ± 0.03 | 0.73 ± 0.02 | 0.79 ± 0.07 | 0.66 ± 0.01
Relative | 5.75 ± 0.17 | 5.77 ± 0.16 | 5.88 ± 0.08 | 6.03 ± 0.11 | 6.68 ± 0.57 | 6.36 ± 0.12
Thymus
Absolute | 0.352 ± 0.020 | 0.354 ± 0.012 | 0.363 ± 0.012 | 0.331 ± 0.015 | 0.347 ± 0.019 | 0.294 ± 0.022
Relative | 2.799 ± 0.155 | 2.774 ± 0.117 | 2.910 ± 0.093 | 2.744 ± 0.108 | 2.927 ± 0.128 | 2.817 ± 0.208

* Significantly different (P ≤ 0.05) from the control group by Williams’ test.

** Significantly different (P ≤ 0.01) from the control group by Williams’ or Dunnett’s test.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Table C-2 Organ Weights and Organ-Weight-to-Body-Weight Ratios for F344/NTac Rats in the Three-month Feed Study of p-Toluenesulfonamide^a^

| 0 ppm | 625 ppm | 1,250 ppm | 2,500 ppm | 5,000 ppm | 10,000 ppm
n | 10 | 10 | 10 | 10 | 10 | 10
Male
Necropsy body wt | 339 ± 7 | 325 ± 5 | 338 ± 6 | 323 ± 7 | 320 ± 6 | 315 ± 8*
Heart
Absolute | 0.99 ± 0.02 | 0.98 ± 0.03 | 1.01 ± 0.03 | 0.99 ± 0.02 | 0.97 ± 0.02 | 0.96 ± 0.03
Relative | 2.91 ± 0.05 | 3.01 ± 0.08 | 2.98 ± 0.04 | 3.06 ± 0.04 | 3.04 ± 0.03 | 3.04 ± 0.04
R. Kidney
Absolute | 1.05 ± 0.02 | 1.05 ± 0.01 | 1.08 ± 0.02 | 1.10 ± 0.03 | 1.12 ± 0.03 | 1.11 ± 0.03
Relative | 3.10 ± 0.04 | 3.25 ± 0.06 | 3.19 ± 0.05 | 3.42 ± 0.04** | 3.51 ± 0.04** | 3.54 ± 0.06**
Liver
Absolute | 11.25 ± 0.30 | 10.72 ± 0.20 | 11.33 ± 0.30 | 10.97 ± 0.21 | 10.94 ± 0.25 | 10.82 ± 0.25
Relative | 33.14 ± 0.48 | 33.03 ± 0.38 | 33.53 ± 0.72 | 34.00 ± 0.37 | 34.15 ± 0.39 | 34.39 ± 0.29
Lung
Absolute | 1.58 ± 0.08 | 1.47 ± 0.03 | 1.56 ± 0.06 | 1.46 ± 0.05 | 1.43 ± 0.06 | 1.50 ± 0.06
Relative | 4.66 ± 0.23 | 4.53 ± 0.12 | 4.61 ± 0.19 | 4.52 ± 0.13 | 4.45 ± 0.14 | 4.76 ± 0.16
R. Testis
Absolute | 1.412 ± 0.016 | 1.408 ± 0.018 | 1.382 ± 0.024 | 1.392 ± 0.039 | 1.412 ± 0.019 | 1.364 ± 0.041
Relative | 4.173 ± 0.071 | 4.340 ± 0.048 | 4.094 ± 0.076 | 4.315 ± 0.085 | 4.417 ± 0.073 | 4.348 ± 0.144
Thymus
Absolute | 0.303 ± 0.012 | 0.270 ± 0.012 | 0.285 ± 0.009 | 0.267 ± 0.009 | 0.273 ± 0.009^b^ | 0.237 ± 0.014**
Relative | 0.893 ± 0.029 | 0.829 ± 0.029 | 0.845 ± 0.025 | 0.834 ± 0.044 | 0.850 ± 0.021^b^ | 0.754 ± 0.042*
Female
Necropsy body wt | 190 ± 3 | 190 ± 2 | 187 ± 4 | 187 ± 2 | 184 ± 3 | 174 ± 2**
Heart
Absolute | 0.64 ± 0.02 | 0.64 ± 0.01 | 0.63 ± 0.02 | 0.62 ± 0.01 | 0.62 ± 0.02 | 0.59 ± 0.01*
Relative | 3.36 ± 0.06 | 3.36 ± 0.06 | 3.33 ± 0.05 | 3.32 ± 0.07 | 3.39 ± 0.05 | 3.37 ± 0.07
R. Kidney
Absolute | 0.66 ± 0.01 | 0.66 ± 0.01 | 0.67 ± 0.02 | 0.69 ± 0.01 | 0.92 ± 0.26 | 0.64 ± 0.01
Relative | 3.49 ± 0.06 | 3.49 ± 0.04 | 3.56 ± 0.03 | 3.69 ± 0.03 | 4.87 ± 1.25 | 3.68 ± 0.04
Liver
Absolute | 5.98 ± 0.11 | 6.06 ± 0.10 | 6.01 ± 0.17 | 5.96 ± 0.11 | 5.90 ± 0.16 | 5.66 ± 0.14
Relative | 31.54 ± 0.33 | 31.95 ± 0.45 | 32.04 ± 0.50 | 31.94 ± 0.40 | 32.10 ± 0.34 | 32.44 ± 0.77
Lung
Absolute | 0.99 ± 0.03 | 1.05 ± 0.04 | 1.00 ± 0.04 | 0.99 ± 0.02 | 0.96 ± 0.04 | 0.93 ± 0.02
Relative | 5.20 ± 0.08 | 5.52 ± 0.16 | 5.34 ± 0.20 | 5.31 ± 0.12 | 5.24 ± 0.16 | 5.33 ± 0.13
Thymus
Absolute | 0.233 ± 0.010 | 0.235 ± 0.008 | 0.229 ± 0.006 | 0.237 ± 0.009 | 0.224 ± 0.006 | 0.212 ± 0.009
Relative | 1.230 ± 0.040 | 1.237 ± 0.037 | 1.222 ± 0.025 | 1.270 ± 0.042 | 1.225 ± 0.037 | 1.215 ± 0.038

* Significantly different (P ≤ 0.05) from the control group by Williams’ or Dunnett’s test.

** Significantly different (P ≤ 0.01) from the control group by Williams’ test.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

^b^ n = 9.

Table C-3 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice in the Two-week Feed Study of p-Toluenesulfonamide^a^

| 0 ppm | 750 ppm | 1,500 ppm | 3,000 ppm | 10,000 ppm | 30,000 ppm
n | 5 | 5 | 5 | 5 | 5 | 5
Male
Necropsy body wt | 24.6 ± 0.5 | 24.7 ± 0.6 | 23.9 ± 0.9 | 24.8 ± 0.4 | 23.9 ± 0.3 | 21.2 ± 0.5**
Heart
Absolute | 0.12 ± 0.00 | 0.12 ± 0.01 | 0.12 ± 0.00 | 0.12 ± 0.00 | 0.12 ± 0.00 | 0.11 ± 0.00
Relative | 4.82 ± 0.04 | 4.96 ± 0.17 | 5.06 ± 0.06 | 4.87 ± 0.05 | 5.06 ± 0.07 | 5.33 ± 0.09**
R. Kidney
Absolute | 0.22 ± 0.01 | 0.23 ± 0.01 | 0.23 ± 0.01 | 0.23 ± 0.01 | 0.25 ± 0.01 | 0.22 ± 0.01
Relative | 9.06 ± 0.28 | 9.11 ± 0.27 | 9.58 ± 0.23 | 9.39 ± 0.32 | 10.38 ± 0.25** | 10.44 ± 0.24**
Liver
Absolute | 1.30 ± 0.02 | 1.22 ± 0.04 | 1.17 ± 0.08 | 1.29 ± 0.04 | 1.24 ± 0.02 | 1.12 ± 0.05
Relative | 52.61 ± 0.67 | 49.39 ± 0.79 | 48.83 ± 1.51 | 52.00 ± 1.08 | 51.95 ± 0.41 | 52.71 ± 1.58
Lung
Absolute | 0.16 ± 0.00 | 0.16 ± 0.00 | 0.17 ± 0.01 | 0.16 ± 0.01 | 0.17 ± 0.00 | 0.16 ± 0.01
Relative | 6.39 ± 0.22 | 6.31 ± 0.06 | 7.06 ± 0.40 | 6.58 ± 0.30 | 7.03 ± 0.14 | 7.40 ± 0.17**
R. Testis
Absolute | 0.100 ± 0.003 | 0.101 ± 0.002 | 0.101 ± 0.003 | 0.101 ± 0.002 | 0.100 ± 0.002 | 0.094 ± 0.001
Relative | 4.054 ± 0.086 | 4.116 ± 0.076 | 4.231 ± 0.096 | 4.083 ± 0.074 | 4.200 ± 0.046 | 4.428 ± 0.107*
Thymus
Absolute | 0.046 ± 0.002 | 0.052 ± 0.002 | 0.044 ± 0.002 | 0.045 ± 0.002 | 0.044 ± 0.003 | 0.030 ± 0.002**
Relative | 1.876 ± 0.053 | 2.103 ± 0.065 | 1.842 ± 0.089 | 1.797 ± 0.048 | 1.851 ± 0.132 | 1.416 ± 0.099**
Female
Necropsy body wt | 19.6 ± 0.5 | 19.3 ± 0.2 | 18.5 ± 0.2 | 19.0 ± 0.4 | 19.1 ± 0.4 | 16.6 ± 0.4**
Heart
Absolute | 0.09 ± 0.00 | 0.09 ± 0.00 | 0.10 ± 0.00 | 0.10 ± 0.00 | 0.10 ± 0.00 | 0.09 ± 0.00
Relative | 4.80 ± 0.10 | 4.79 ± 0.17 | 5.15 ± 0.08 | 5.01 ± 0.13 | 5.27 ± 0.07* | 5.37 ± 0.11**
R. Kidney
Absolute | 0.13 ± 0.01 | 0.13 ± 0.00 | 0.14 ± 0.00 | 0.14 ± 0.00 | 0.15 ± 0.00* | 0.14 ± 0.00*
Relative | 6.64 ± 0.19 | 6.77 ± 0.13 | 7.38 ± 0.13** | 7.22 ± 0.07** | 8.01 ± 0.08** | 8.30 ± 0.14**
Liver
Absolute | 0.99 ± 0.05 | 0.91 ± 0.02 | 0.93 ± 0.02 | 0.99 ± 0.05 | 1.04 ± 0.03 | 0.78 ± 0.02**
Relative | 50.23 ± 1.41 | 47.10 ± 0.90 | 50.06 ± 0.74 | 51.85 ± 1.50 | 54.33 ± 1.03* | 47.07 ± 0.48
Lung
Absolute | 0.14 ± 0.00 | 0.15 ± 0.00 | 0.14 ± 0.00 | 0.13 ± 0.01 | 0.14 ± 0.00 | 0.13 ± 0.00
Relative | 7.16 ± 0.14 | 7.56 ± 0.09 | 7.56 ± 0.19 | 6.69 ± 0.58 | 7.27 ± 0.06 | 7.85 ± 0.27
Thymus
Absolute | 0.063 ± 0.004 | 0.063 ± 0.003 | 0.066 ± 0.001 | 0.068 ± 0.003 | 0.066 ± 0.002 | 0.046 ± 0.002**
Relative | 3.229 ± 0.232 | 3.279 ± 0.208 | 3.579 ± 0.054 | 3.578 ± 0.117 | 3.453 ± 0.049 | 2.788 ± 0.165

* Significantly different (P ≤ 0.05) from the control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).

Table C-4 Organ Weights and Organ-Weight-to-Body-Weight Ratios for Mice in the Three-month Feed Study of p-Toluenesulfonamide^a^

| 0 ppm | 625 ppm | 1,250 ppm | 2,500 ppm | 5,000 ppm | 10,000 ppm
Male
n | 10 | 10 | 10 | 10 | 10 | 10
Necropsy body wt | 32.1 ± 0.7 | 31.8 ± 0.9 | 32.4 ± 1.1 | 31.7 ± 0.9 | 30.8 ± 0.8 | 30.0 ± 0.7
Heart
Absolute | 0.15 ± 0.00 | 0.15 ± 0.00 | 0.15 ± 0.00 | 0.15 ± 0.00 | 0.16 ± 0.00* | 0.15 ± 0.00
Relative | 4.54 ± 0.10 | 4.75 ± 0.13 | 4.76 ± 0.14 | 4.75 ± 0.14 | 5.15 ± 0.13** | 5.06 ± 0.12**
R. Kidney
Absolute | 0.26 ± 0.01 | 0.27 ± 0.01 | 0.28 ± 0.01 | 0.26 ± 0.01 | 0.28 ± 0.01 | 0.28 ± 0.01
Relative | 8.06 ± 0.22 | 8.56 ± 0.18 | 8.56 ± 0.16 | 8.32 ± 0.26 | 9.17 ± 0.41** | 9.26 ± 0.18**
Liver
Absolute | 1.36 ± 0.03 | 1.40 ± 0.03 | 1.42 ± 0.04 | 1.33 ± 0.04 | 1.34 ± 0.04 | 1.33 ± 0.03
Relative | 42.26 ± 0.71 | 43.93 ± 0.43 | 43.83 ± 0.47 | 41.82 ± 0.48 | 43.48 ± 0.85 | 44.36 ± 0.64
Lung
Absolute | 0.21 ± 0.02 | 0.22 ± 0.02 | 0.23 ± 0.01 | 0.20 ± 0.01 | 0.23 ± 0.02 | 0.25 ± 0.02
Relative | 6.51 ± 0.52 | 6.80 ± 0.40 | 7.12 ± 0.32 | 6.35 ± 0.21 | 7.45 ± 0.48 | 8.24 ± 0.51*
R. Testis
Absolute | 0.110 ± 0.002 | 0.112 ± 0.002 | 0.115 ± 0.001 | 0.115 ± 0.001 | 0.116 ± 0.002 | 0.113 ± 0.003
Relative | 3.445 ± 0.084 | 3.560 ± 0.132 | 3.593 ± 0.113 | 3.637 ± 0.106 | 3.796 ± 0.095* | 3.782 ± 0.075*
Thymus
Absolute | 0.039 ± 0.003 | 0.038 ± 0.003 | 0.036 ± 0.003 | 0.036 ± 0.002 | 0.035 ± 0.001 | 0.032 ± 0.003
Relative | 1.199 ± 0.082 | 1.198 ± 0.069 | 1.089 ± 0.061 | 1.129 ± 0.062 | 1.155 ± 0.060 | 1.075 ± 0.111
Female
n | 10 | 10 | 10 | 10 | 10 | 9
Necropsy body wt | 24.8 ± 0.5 | 26.7 ± 0.6 | 27.1 ± 0.5* | 26.4 ± 0.6 | 25.4 ± 0.5 | 24.8 ± 0.7
Heart
Absolute | 0.12 ± 0.00 | 0.12 ± 0.00 | 0.13 ± 0.00 | 0.12 ± 0.00 | 0.12 ± 0.00 | 0.13 ± 0.00
Relative | 4.88 ± 0.15 | 4.66 ± 0.09 | 4.66 ± 0.12 | 4.58 ± 0.10 | 4.69 ± 0.13 | 5.08 ± 0.13
R. Kidney
Absolute | 0.16 ± 0.00 | 0.16 ± 0.00 | 0.17 ± 0.00 | 0.16 ± 0.01 | 0.17 ± 0.00 | 0.18 ± 0.01**
Relative | 6.42 ± 0.15 | 6.14 ± 0.12 | 6.23 ± 0.13 | 6.08 ± 0.15 | 6.61 ± 0.12 | 7.31 ± 0.16**
Liver
Absolute | 1.02 ± 0.02 | 1.13 ± 0.02* | 1.15 ± 0.03** | 1.09 ± 0.03 | 1.07 ± 0.03 | 1.12 ± 0.04
Relative | 41.14 ± 0.87 | 42.36 ± 0.61 | 42.61 ± 0.63 | 41.44 ± 0.92 | 42.01 ± 0.47 | 45.15 ± 1.03**
Lung
Absolute | 0.19 ± 0.01 | 0.20 ± 0.01 | 0.20 ± 0.01 | 0.21 ± 0.01 | 0.19 ± 0.01 | 0.21 ± 0.01
Relative | 7.68 ± 0.45 | 7.34 ± 0.40 | 7.34 ± 0.45 | 7.83 ± 0.43 | 7.30 ± 0.29 | 8.50 ± 0.29
Thymus
Absolute | 0.047 ± 0.002 | 0.046 ± 0.003 | 0.043 ± 0.002 | 0.045 ± 0.002 | 0.044 ± 0.003 | 0.039 ± 0.004
Relative | 1.883 ± 0.086 | 1.711 ± 0.097 | 1.596 ± 0.068 | 1.696 ± 0.067 | 1.709 ± 0.102 | 1.564 ± 0.131

* Significantly different (P ≤ 0.05) from the control group by Williams’ or Dunnett’s test.

** P ≤ 0.01.

^a^ Organ weights (absolute weights) and body weights are given in grams; organ-weight-to-body-weight ratios (relative weights) are given as mg organ weight/g body weight (mean ± standard error).