# Appendix B Clinical Pathology Results

Table B-1 Hematology and Clinical Chemistry Data for F344/NTac Rats in the Three-month Feed Study of p-Toluenesulfonamide^a^

| 0 ppm | 625 ppm | 1,250 ppm | 2,500 ppm | 5,000 ppm | 10,000 ppm
Male
Hematology
n
Day 3 | 10 | 10 | 10 | 10 | 10 | 10
Day 22 | 10 | 9 | 10 | 10 | 10 | 10
Week 14 | 10 | 10 | 10 | 9 | 10 | 10
Hematocrit (auto) (%)
Day 3 | 39.7 ± 0.9 | 40.8 ± 0.7 | 40.2 ± 0.7 | 40.4 ± 0.5 | 40.9 ± 0.7 | 40.7 ± 0.7
Day 22 | 46.5 ± 0.7 | 48.7 ± 1.8 | 47.6 ± 0.6 | 45.6 ± 0.8 | 45.4 ± 1.0 | 45.4 ± 0.7
Week 14 | 44.9 ± 0.4 | 45.7 ± 0.5 | 45.6 ± 0.4 | 44.9 ± 0.4 | 45.0 ± 0.4 | 44.2 ± 0.3
Manual hematocrit (%)
Day 3 | 49.4 ± 0.6 | 50.4 ± 0.8 | 49.7 ± 0.8 | 50.5 ± 0.7 | 49.7 ± 0.4 | 50.7 ± 0.9
Day 22 | 48.7 ± 0.4 | 50.0 ± 1.9 | 49.7 ± 0.7 | 50.2 ± 1.1 | 48.7 ± 0.7 | 47.3 ± 0.4
Week 14 | 48.9 ± 0.4 | 50.1 ± 0.4 | 49.2 ± 0.5 | 48.7 ± 0.3 | 49.1 ± 0.3 | 48.5 ± 0.3
Hemoglobin (g/dL)
Day 3 | 13.3 ± 0.3 | 13.6 ± 0.2 | 13.5 ± 0.2 | 13.6 ± 0.1 | 13.7 ± 0.2 | 13.8 ± 0.2
Day 22 | 15.5 ± 0.2 | 16.2 ± 0.6 | 15.8 ± 0.2 | 15.2 ± 0.2 | 15.1 ± 0.3 | 15.2 ± 0.2
Week 14 | 15.1 ± 0.1 | 15.3 ± 0.2 | 15.3 ± 0.1 | 15.0 ± 0.1 | 15.0 ± 0.1 | 14.9 ± 0.1
Erythrocytes (10^6^/μL)
Day 3 | 7.03 ± 0.16 | 7.11 ± 0.13 | 7.15 ± 0.16 | 7.09 ± 0.10 | 7.29 ± 0.13 | 7.29 ± 0.14
Day 22 | 8.40 ± 0.14 | 8.72 ± 0.29 | 8.55 ± 0.12 | 8.18 ± 0.15 | 8.24 ± 0.15 | 8.29 ± 0.13
Week 14 | 9.16 ± 0.08 | 9.23 ± 0.08 | 9.11 ± 0.09 | 9.20 ± 0.07 | 9.12 ± 0.09 | 8.97 ± 0.05
Erythrocyte distribution width (%)
Day 3 | 14.91 ± 0.31 | 14.98 ± 0.42 | 15.40 ± 0.35 | 14.67 ± 0.30 | 15.49 ± 0.28 | 14.41 ± 0.39
Day 22 | 13.19 ± 0.12 | 13.26 ± 0.16 | 12.80 ± 0.11 | 13.28 ± 0.19 | 13.30 ± 0.06 | 12.91 ± 0.14
Week 14 | 13.75 ± 0.16 | 13.57 ± 0.14 | 13.81 ± 0.13 | 13.61 ± 0.15 | 14.04 ± 0.12 | 13.44 ± 0.14
Reticulocytes (10^3^/μL)
Day 3 | 211 ± 6 | 230 ± 10 | 239 ± 10 | 229 ± 9 | 234 ± 10^b^ | 214 ± 9
Day 22 | 349 ± 14 | 370 ± 30 | 370 ± 9 | 362 ± 8 | 352 ± 16 | 360 ± 17
Week 14 | 266 ± 15 | 275 ± 14 | 293 ± 9 | 270 ± 12 | 293 ± 13 | 265 ± 15
Reticulocytes (%)
Day 3 | 3.00 ± 0.07 | 3.23 ± 0.11 | 3.34 ± 0.11 | 3.23 ± 0.12 | 3.21 ± 0.08^b^ | 2.93 ± 0.11
Day 22 | 4.17 ± 0.19 | 4.20 ± 0.21 | 4.34 ± 0.13 | 4.43 ± 0.12 | 4.27 ± 0.15 | 4.35 ± 0.23
Week 14 | 2.91 ± 0.17 | 2.98 ± 0.17 | 3.21 ± 0.09 | 2.93 ± 0.12 | 3.21 ± 0.13 | 2.96 ± 0.17
Nucleated erythrocytes/100 leukocytes
Day 3 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Day 22 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Week 14 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Mean cell volume (fL)
Day 3 | 56.6 ± 0.3 | 57.4 ± 0.2 | 56.3 ± 0.3 | 57.1 ± 0.2 | 56.2 ± 0.3 | 55.9 ± 0.4
Day 22 | 55.3 ± 0.2 | 55.8 ± 0.4 | 55.9 ± 0.2 | 55.8 ± 0.2 | 55.1 ± 0.3 | 54.7 ± 0.3
Week 14 | 49.2 ± 0.3 | 49.4 ± 0.3 | 49.9 ± 0.5 | 48.8 ± 0.2 | 49.4 ± 0.2 | 49.3 ± 0.2
Mean cell hemoglobin (pg)
Day 3 | 18.9 ± 0.1 | 19.2 ± 0.1 | 18.9 ± 0.1 | 19.2 ± 0.1 | 18.8 ± 0.2 | 18.9 ± 0.1
Day 22 | 18.4 ± 0.1 | 18.5 ± 0.1 | 18.6 ± 0.1 | 18.5 ± 0.1 | 18.3 ± 0.1 | 18.3 ± 0.1
Week 14 | 16.4 ± 0.1 | 16.6 ± 0.1 | 16.8 ± 0.2 | 16.3 ± 0.1 | 16.5 ± 0.0 | 16.6 ± 0.1
Mean cell hemoglobin concentration (g/dL)
Day 3 | 33.5 ± 0.1 | 33.4 ± 0.1 | 33.5 ± 0.1 | 33.6 ± 0.1 | 33.4 ± 0.1 | 33.8 ± 0.1
Day 22 | 33.3 ± 0.1 | 33.2 ± 0.1 | 33.3 ± 0.1 | 33.3 ± 0.1 | 33.3 ± 0.1 | 33.4 ± 0.1
Week 14 | 33.5 ± 0.1 | 33.6 ± 0.1 | 33.5 ± 0.1 | 33.4 ± 0.1 | 33.4 ± 0.1 | 33.6 ± 0.1
Platelets (10^3^/μL)
Day 3 | 798.0 ± 23.0 | 781.0 ± 16.0 | 827.0 ± 21.0 | 814.0 ± 23.0 | 862.0 ± 24.0 | 839.0 ± 16.0
Day 22 | 780.0 ± 11.0 | 746.0 ± 24.0 | 769.0 ± 16.0 | 777.0 ± 9.0 | 754.0 ± 11.0 | 692.0 ± 29.0**
Week 14 | 594.0 ± 15.0 | 609.0 ± 12.0 | 600.0 ± 8.0 | 594.0 ± 21.0 | 598.0 ± 17.0 | 599.0 ± 14.0
Mean platelet volume (μm^3^)
Day 3 | 6.360 ± 0.050 | 6.390 ± 0.066 | 6.370 ± 0.058 | 6.440 ± 0.058 | 6.370 ± 0.021 | 6.430 ± 0.070
Day 22 | 6.430 ± 0.063 | 6.489 ± 0.093 | 6.440 ± 0.050 | 6.210 ± 0.055 | 6.410 ± 0.091 | 6.400 ± 0.116
Week 14 | 6.430 ± 0.072 | 6.360 ± 0.048 | 6.380 ± 0.059 | 6.411 ± 0.026 | 6.380 ± 0.066 | 6.330 ± 0.054
Leukocytes (10^3^/μL)
Day 3 | 7.71 ± 0.42 | 8.11 ± 0.48 | 7.64 ± 0.40 | 8.05 ± 0.44 | 8.08 ± 0.30 | 7.76 ± 0.32
Day 22 | 11.87 ± 0.35 | 10.82 ± 0.41 | 12.02 ± 0.49 | 12.35 ± 0.48 | 11.21 ± 0.36 | 11.50 ± 0.39
Week 14 | 10.45 ± 0.94 | 11.57 ± 0.61 | 9.94 ± 0.46 | 10.77 ± 0.44 | 10.95 ± 0.62 | 10.51 ± 0.79
Segmented neutrophils (10^3^/μL)
Day 3 | 1.84 ± 0.15 | 1.61 ± 0.12 | 1.58 ± 0.08 | 1.63 ± 0.08 | 1.53 ± 0.07 | 1.36 ± 0.05**
Day 22 | 2.57 ± 0.10 | 2.04 ± 0.15 | 2.34 ± 0.19 | 2.33 ± 0.11 | 2.09 ± 0.10* | 2.21 ± 0.14
Week 14 | 2.46 ± 0.28 | 2.54 ± 0.18 | 2.52 ± 0.16 | 2.28 ± 0.12 | 2.46 ± 0.24 | 2.47 ± 0.19
Bands (10^3^/μL)
Day 3 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Day 22 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Week 14 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Metamyelocyte (10^3^/μL)
Day 3 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Day 22 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 14 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Myelocyte (10^3^/μL)
Day 3 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Day 22 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 14 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Lymphocytes (10^3^/μL)
Day 3 | 5.49 ± 0.23 | 6.13 ± 0.35 | 5.74 ± 0.32 | 6.07 ± 0.35 | 6.19 ± 0.21 | 6.05 ± 0.25
Day 22 | 8.73 ± 0.26 | 8.24 ± 0.29 | 9.10 ± 0.37 | 9.42 ± 0.37 | 8.56 ± 0.33 | 8.66 ± 0.26
Week 14 | 7.45 ± 0.60 | 8.41 ± 0.40 | 6.84 ± 0.34 | 7.93 ± 0.32 | 7.89 ± 0.44 | 7.38 ± 0.55
Atypical lymphocytes (10^3^/μL)
Day 3 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Day 22 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Week 14 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Monocytes (10^3^/μL)
Day 3 | 0.21 ± 0.05 | 0.21 ± 0.01 | 0.17 ± 0.02 | 0.20 ± 0.02 | 0.21 ± 0.02 | 0.20 ± 0.02
Day 22 | 0.28 ± 0.02 | 0.25 ± 0.01 | 0.30 ± 0.02 | 0.31 ± 0.03 | 0.27 ± 0.01 | 0.31 ± 0.01
Week 14 | 0.26 ± 0.05 | 0.33 ± 0.04 | 0.32 ± 0.03 | 0.30 ± 0.03 | 0.32 ± 0.03 | 0.33 ± 0.04
Basophils (10^3^/μL)
Day 3 | 0.131 ± 0.018 | 0.135 ± 0.009 | 0.117 ± 0.013 | 0.119 ± 0.013 | 0.124 ± 0.010 | 0.122 ± 0.011
Day 22 | 0.234 ± 0.014 | 0.240 ± 0.023 | 0.236 ± 0.019 | 0.247 ± 0.025 | 0.232 ± 0.010 | 0.264 ± 0.032
Week 14 | 0.186 ± 0.029 | 0.212 ± 0.024 | 0.183 ± 0.016 | 0.189 ± 0.010 | 0.200 ± 0.019 | 0.236 ± 0.041
Eosinophils (10^3^/μL)
Day 3 | 0.03 ± 0.01 | 0.03 ± 0.00 | 0.03 ± 0.00 | 0.03 ± 0.00 | 0.03 ± 0.00 | 0.03 ± 0.01
Day 22 | 0.06 ± 0.01 | 0.05 ± 0.01 | 0.05 ± 0.01 | 0.05 ± 0.01 | 0.06 ± 0.01 | 0.06 ± 0.01
Week 14 | 0.10 ± 0.01 | 0.08 ± 0.01 | 0.08 ± 0.01 | 0.07 ± 0.01 | 0.08 ± 0.01 | 0.09 ± 0.02
Clinical Chemistry
n | 10 | 10 | 10 | 10 | 10 | 10
Urea nitrogen (mg/dL)
Day 3 | 13.9 ± 0.4 | 13.2 ± 0.7 | 13.3 ± 0.8 | 12.7 ± 0.4 | 11.0 ± 0.3** | 11.6 ± 0.5**
Day 22 | 12.5 ± 0.3 | 12.2 ± 0.5 | 12.2 ± 0.3 | 10.6 ± 0.4* | 11.3 ± 0.4 | 13.0 ± 0.5
Week 14 | 20.4 ± 0.5 | 18.7 ± 0.6 | 20.3 ± 0.7 | 18.3 ± 0.5* | 17.0 ± 0.6** | 18.3 ± 0.6**
Creatinine (mg/dL)
Day 3 | 0.60 ± 0.01 | 0.59 ± 0.01 | 0.60 ± 0.00 | 0.60 ± 0.00 | 0.60 ± 0.00 | 0.63 ± 0.02
Day 22 | 0.61 ± 0.01 | 0.61 ± 0.01 | 0.62 ± 0.01 | 0.61 ± 0.01 | 0.60 ± 0.00 | 0.60 ± 0.00
Week 14 | 0.87 ± 0.02 | 0.84 ± 0.02 | 0.87 ± 0.02 | 0.84 ± 0.02 | 0.81 ± 0.01* | 0.87 ± 0.02
Total protein (g/dL)
Day 3 | 5.3 ± 0.1 | 5.4 ± 0.1 | 5.4 ± 0.1 | 5.3 ± 0.0 | 5.3 ± 0.1 | 5.5 ± 0.1
Day 22 | 6.2 ± 0.1 | 6.1 ± 0.1 | 6.2 ± 0.0 | 6.0 ± 0.1* | 6.0 ± 0.1* | 5.9 ± 0.1**
Week 14 | 7.5 ± 0.1 | 7.7 ± 0.1 | 7.5 ± 0.1 | 7.6 ± 0.1 | 7.5 ± 0.1 | 7.6 ± 0.1
Albumin (g/dL)
Day 3 | 3.4 ± 0.0 | 3.4 ± 0.0 | 3.5 ± 0.1 | 3.4 ± 0.0 | 3.4 ± 0.0 | 3.5 ± 0.0
Day 22 | 3.7 ± 0.0 | 3.6 ± 0.0 | 3.7 ± 0.0 | 3.6 ± 0.0 | 3.6 ± 0.0* | 3.5 ± 0.1*
Week 14 | 4.0 ± 0.0 | 4.0 ± 0.1 | 4.0 ± 0.0 | 4.0 ± 0.0 | 4.0 ± 0.0 | 4.1 ± 0.0
Alanine aminotransferase (IU/L)
Day 3 | 81 ± 3 | 74 ± 2 | 80 ± 2 | 75 ± 2 | 75 ± 3 | 77 ± 3
Day 22 | 67 ± 1 | 62 ± 2* | 61 ± 1** | 60 ± 1** | 60 ± 2** | 59 ± 1**
Week 14 | 110 ± 9 | 90 ± 5 | 93 ± 6 | 83 ± 5* | 68 ± 3** | 66 ± 2**
Alkaline phosphatase (IU/L)
Day 3 | 839 ± 18 | 840 ± 15 | 857 ± 25 | 861 ± 13 | 892 ± 11* | 891 ± 14*
Day 22 | 605 ± 15 | 613 ± 21 | 626 ± 13 | 633 ± 13 | 632 ± 12 | 638 ± 10
Week 14 | 305 ± 8 | 329 ± 8* | 341 ± 10** | 326 ± 8* | 333 ± 9* | 347 ± 7**
Creatine kinase (IU/L)
Day 3 | 470 ± 54 | 436 ± 57 | 466 ± 58 | 455 ± 36 | 407 ± 35 | 537 ± 85
Day 22 | 232 ± 31 | 317 ± 63 | 234 ± 38 | 276 ± 36 | 243 ± 35 | 240 ± 40
Week 14 | 553 ± 76 | 701 ± 95 | 624 ± 76 | 941 ± 211 | 653 ± 88 | 826 ± 133
Sorbitol dehydrogenase (IU/L)
Day 3 | 35 ± 2 | 39 ± 2 | 36 ± 2 | 38 ± 1 | 37 ± 1 | 32 ± 3
Day 22 | 31 ± 2 | 28 ± 3 | 30 ± 2 | 28 ± 1 | 29 ± 2 | 27 ± 2
Week 14 | 85 ± 9 | 69 ± 8 | 78 ± 8 | 63 ± 8* | 60 ± 9* | 60 ± 8*
Bile acids (μmol/L)
Day 3 | 51.0 ± 5.2 | 56.7 ± 6.7 | 57.5 ± 8.2 | 46.4 ± 7.5 | 70.9 ± 4.7 | 54.5 ± 7.0
Day 22 | 29.8 ± 5.6 | 26.2 ± 3.5 | 37.1 ± 4.4 | 44.3 ± 9.5 | 44.5 ± 3.2 | 28.7 ± 4.0
Week 14 | 14.0 ± 2.2 | 12.9 ± 2.1 | 12.1 ± 1.2 | 11.6 ± 1.0 | 22.7 ± 3.2* | 22.0 ± 2.9*
Female
Hematology
n
Day 3 | 10 | 10 | 10 | 10 | 10 | 10
Day 22 | 10 | 10 | 10 | 10 | 10 | 10
Week 14 | 10 | 10 | 10 | 9 | 10 | 10
Hematocrit (auto) (%)
Day 3 | 42.3 ± 0.4 | 42.1 ± 0.8 | 42.5 ± 0.7 | 42.8 ± 0.6 | 43.1 ± 0.6 | 42.4 ± 0.9
Day 22 | 46.2 ± 0.6 | 46.3 ± 0.5 | 46.8 ± 0.4 | 45.2 ± 1.0 | 46.2 ± 0.5 | 47.4 ± 0.5
Week 14 | 44.2 ± 0.3 | 42.2 ± 2.2 | 44.1 ± 0.4 | 45.0 ± 0.4 | 43.5 ± 0.4 | 42.3 ± 0.6*
Manual hematocrit (%)
Day 3 | 52.6 ± 0.5 | 51.9 ± 0.6 | 54.3 ± 1.1 | 53.6 ± 0.8 | 53.2 ± 0.6 | 53.5 ± 0.8
Day 22 | 50.9 ± 0.9 | 50.8 ± 0.5 | 51.2 ± 0.6 | 50.6 ± 0.6 | 50.7 ± 0.7 | 51.7 ± 0.4
Week 14 | 49.2 ± 0.4 | 49.7 ± 0.3 | 49.1 ± 0.3 | 49.9 ± 0.4 | 48.9 ± 0.4 | 47.6 ± 0.7
Hemoglobin (g/dL)
Day 3 | 14.5 ± 0.1 | 14.4 ± 0.2 | 14.6 ± 0.2 | 14.7 ± 0.2 | 14.7 ± 0.2 | 14.7 ± 0.3
Day 22 | 16.2 ± 0.2 | 16.1 ± 0.2 | 16.4 ± 0.1 | 15.8 ± 0.3 | 16.1 ± 0.2 | 16.4 ± 0.1
Week 14 | 15.3 ± 0.1 | 14.7 ± 0.7 | 15.3 ± 0.1 | 15.5 ± 0.1 | 15.1 ± 0.1 | 14.6 ± 0.2**
Erythrocytes (10^6^/μL)
Day 3 | 7.50 ± 0.07 | 7.62 ± 0.16 | 7.57 ± 0.13 | 7.65 ± 0.13 | 7.68 ± 0.12 | 7.64 ± 0.15
Day 22 | 8.38 ± 0.13 | 8.49 ± 0.08 | 8.50 ± 0.07 | 8.22 ± 0.16 | 8.40 ± 0.09 | 8.75 ± 0.10*
Week 14 | 8.74 ± 0.05 | 8.29 ± 0.41 | 8.62 ± 0.06 | 8.83 ± 0.09 | 8.53 ± 0.09 | 8.37 ± 0.13*
Erythrocyte distribution width (%)
Day 3 | 13.71 ± 0.20 | 14.67 ± 0.49 | 13.99 ± 0.35 | 14.31 ± 0.40 | 14.09 ± 0.30 | 13.91 ± 0.37
Day 22 | 11.97 ± 0.12 | 11.96 ± 0.12 | 11.99 ± 0.20 | 12.10 ± 0.15 | 11.99 ± 0.18 | 12.00 ± 0.14
Week 14 | 11.55 ± 0.07 | 11.42 ± 0.15 | 11.51 ± 0.09 | 11.47 ± 0.10 | 11.38 ± 0.06 | 11.43 ± 0.13
Reticulocytes (10^3^/μL)
Day 3 | 326 ± 12 | 330 ± 13 | 324 ± 10 | 334 ± 9 | 334 ± 10 | 335 ± 12
Day 22 | 176 ± 16 | 189 ± 12 | 183 ± 23 | 188 ± 15 | 192 ± 18 | 218 ± 25
Week 14 | 249 ± 17 | 223 ± 15 | 218 ± 8 | 243 ± 6 | 269 ± 15 | 240 ± 14
Reticulocytes (%)
Day 3 | 4.33 ± 0.13 | 4.32 ± 0.13 | 4.28 ± 0.10 | 4.37 ± 0.13 | 4.34 ± 0.08 | 4.37 ± 0.11
Day 22 | 2.09 ± 0.17 | 2.22 ± 0.13 | 2.16 ± 0.28 | 2.31 ± 0.22 | 2.29 ± 0.22 | 2.48 ± 0.26
Week 14 | 2.85 ± 0.19 | 2.70 ± 0.14 | 2.53 ± 0.10 | 2.76 ± 0.07 | 3.15 ± 0.16 | 2.87 ± 0.17
Nucleated erythrocytes/100 leukocytes
Day 3 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Day 22 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Week 14 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Mean cell volume (fL)
Day 3 | 56.2 ± 0.3 | 55.3 ± 0.3 | 56.2 ± 0.3 | 55.9 ± 0.2 | 56.0 ± 0.3 | 55.5 ± 0.3
Day 22 | 55.3 ± 0.2 | 54.4 ± 0.3 | 55.1 ± 0.3 | 55.0 ± 0.2 | 54.9 ± 0.3 | 54.2 ± 0.2*
Week 14 | 50.6 ± 0.2 | 50.8 ± 0.2 | 51.1 ± 0.2 | 51.0 ± 0.2 | 51.1 ± 0.1 | 50.4 ± 0.2
Mean cell hemoglobin (pg)
Day 3 | 19.4 ± 0.1 | 18.9 ± 0.1 | 19.2 ± 0.1 | 19.2 ± 0.1 | 19.2 ± 0.1 | 19.2 ± 0.1
Day 22 | 19.3 ± 0.1 | 19.0 ± 0.1 | 19.3 ± 0.1 | 19.2 ± 0.1 | 19.2 ± 0.1 | 18.8 ± 0.1*
Week 14 | 17.5 ± 0.1 | 17.7 ± 0.1 | 17.7 ± 0.0* | 17.6 ± 0.1 | 17.7 ± 0.1 | 17.4 ± 0.1
Mean cell hemoglobin concentration (g/dL)
Day 3 | 34.4 ± 0.1 | 34.3 ± 0.1 | 34.3 ± 0.1 | 34.4 ± 0.1 | 34.2 ± 0.1 | 34.6 ± 0.1
Day 22 | 35.0 ± 0.1 | 34.8 ± 0.1 | 35.0 ± 0.1 | 34.9 ± 0.2 | 34.9 ± 0.1 | 34.7 ± 0.1
Week 14 | 34.6 ± 0.1 | 34.8 ± 0.1 | 34.7 ± 0.1 | 34.5 ± 0.1 | 34.7 ± 0.1 | 34.5 ± 0.1
Platelets (10^3^/μL)
Day 3 | 695.0 ± 13.0 | 725.0 ± 14.0 | 708.0 ± 21.0 | 761.0 ± 16.0* | 733.0 ± 16.0* | 780.0 ± 20.0**
Day 22 | 666.0 ± 20.0 | 701.0 ± 16.0 | 679.0 ± 14.0 | 644.0 ± 21.0 | 674.0 ± 12.0 | 597.0 ± 20.0
Week 14 | 638.0 ± 11.0 | 592.0 ± 27.0 | 625.0 ± 18.0 | 605.0 ± 17.0 | 652.0 ± 10.0 | 654.0 ± 10.0
Mean platelet volume (μm^3^)
Day 3 | 6.220 ± 0.042 | 6.380 ± 0.084 | 6.300 ± 0.068 | 6.400 ± 0.115 | 6.290 ± 0.069 | 6.320 ± 0.080
Day 22 | 6.160 ± 0.048 | 6.370 ± 0.122 | 6.320 ± 0.051 | 6.310 ± 0.111 | 6.150 ± 0.064 | 6.230 ± 0.101
Week 14 | 6.820 ± 0.083 | 7.070 ± 0.110 | 6.820 ± 0.149 | 6.789 ± 0.181 | 6.940 ± 0.139 | 6.790 ± 0.147
Leukocytes (10^3^/μL)
Day 3 | 10.25 ± 0.39 | 10.48 ± 0.44 | 10.17 ± 0.37 | 10.64 ± 0.32 | 10.20 ± 0.32 | 10.13 ± 0.38
Day 22 | 12.60 ± 0.36 | 12.74 ± 0.49 | 12.78 ± 0.23 | 11.69 ± 0.38 | 12.11 ± 0.54 | 12.18 ± 0.32
Week 14 | 11.38 ± 0.48 | 12.03 ± 0.49 | 11.55 ± 0.66 | 11.37 ± 0.41 | 11.97 ± 0.52 | 10.96 ± 0.63
Segmented neutrophils (10^3^/μL)
Day 3 | 1.96 ± 0.13 | 1.96 ± 0.14 | 1.74 ± 0.07 | 1.84 ± 0.05 | 1.63 ± 0.08 | 1.53 ± 0.07**
Day 22 | 2.50 ± 0.08 | 2.46 ± 0.14 | 2.27 ± 0.09 | 2.09 ± 0.10* | 2.06 ± 0.18* | 2.16 ± 0.09*
Week 14 | 2.94 ± 0.15 | 2.86 ± 0.19 | 2.87 ± 0.23 | 2.81 ± 0.16 | 2.79 ± 0.22 | 2.47 ± 0.17
Bands (10^3^/μL)
Day 3 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Day 22 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Week 14 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Metamyelocyte (10^3^/μL)
Day 3 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Day 22 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 14 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Myelocyte (10^3^/μL)
Day 3 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Day 22 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Week 14 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000^b^
Lymphocytes (10^3^/μL)
Day 3 | 7.87 ± 0.28 | 8.06 ± 0.31 | 8.02 ± 0.32 | 8.32 ± 0.29 | 8.12 ± 0.26 | 8.15 ± 0.33
Day 22 | 9.49 ± 0.28 | 9.68 ± 0.35 | 9.85 ± 0.17 | 9.03 ± 0.27 | 9.45 ± 0.35 | 9.47 ± 0.23
Week 14 | 7.72 ± 0.33 | 8.35 ± 0.36 | 7.84 ± 0.42 | 7.74 ± 0.31 | 8.44 ± 0.28 | 7.82 ± 0.42
Atypical lymphocytes (10^3^/μL)
Day 3 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Day 22 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Week 14 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Monocytes (10^3^/μL)
Day 3 | 0.21 ± 0.02 | 0.25 ± 0.02 | 0.23 ± 0.01 | 0.26 ± 0.01 | 0.24 ± 0.02 | 0.25 ± 0.02
Day 22 | 0.28 ± 0.02 | 0.30 ± 0.02 | 0.33 ± 0.01 | 0.28 ± 0.02 | 0.30 ± 0.03 | 0.28 ± 0.02
Week 14 | 0.37 ± 0.04 | 0.45 ± 0.03 | 0.46 ± 0.05 | 0.46 ± 0.03 | 0.43 ± 0.05 | 0.37 ± 0.04
Basophils (10^3^/μL)
Day 3 | 0.168 ± 0.011 | 0.179 ± 0.014 | 0.157 ± 0.010 | 0.177 ± 0.007 | 0.174 ± 0.014 | 0.161 ± 0.013
Day 22 | 0.264 ± 0.017 | 0.241 ± 0.018 | 0.265 ± 0.012 | 0.213 ± 0.015 | 0.242 ± 0.014 | 0.218 ± 0.015
Week 14 | 0.266 ± 0.022 | 0.288 ± 0.022 | 0.292 ± 0.034 | 0.260 ± 0.017 | 0.236 ± 0.022 | 0.231 ± 0.026
Eosinophils (10^3^/μL)
Day 3 | 0.04 ± 0.00 | 0.04 ± 0.00 | 0.03 ± 0.00 | 0.04 ± 0.00 | 0.05 ± 0.00 | 0.04 ± 0.00
Day 22 | 0.06 ± 0.01 | 0.06 ± 0.01 | 0.07 ± 0.01 | 0.07 ± 0.01 | 0.07 ± 0.01 | 0.06 ± 0.00
Week 14 | 0.09 ± 0.01 | 0.08 ± 0.01 | 0.10 ± 0.01 | 0.10 ± 0.01 | 0.08 ± 0.02 | 0.08 ± 0.01
Clinical Chemistry
n
Day 3 | 10 | 10 | 10 | 10 | 10 | 10
Day 22 | 9 | 10 | 10 | 10 | 10 | 10
Week 14 | 10 | 10 | 10 | 10 | 10 | 10
Urea nitrogen (mg/dL)
Day 3 | 12.5 ± 0.4 | 13.3 ± 0.3 | 14.2 ± 0.5 | 14.0 ± 0.6 | 13.2 ± 0.6 | 13.9 ± 0.5
Day 22 | 14.0 ± 0.3 | 14.6 ± 0.4 | 14.8 ± 0.4 | 15.5 ± 0.6 | 14.0 ± 0.5 | 15.1 ± 0.7
Week 14 | 19.4 ± 0.3 | 18.1 ± 0.5 | 17.9 ± 0.7 | 18.5 ± 0.7 | 19.1 ± 0.9 | 18.6 ± 0.7
Creatinine (mg/dL)
Day 3 | 0.60 ± 0.00 | 0.60 ± 0.00 | 0.61 ± 0.01 | 0.61 ± 0.01 | 0.60 ± 0.00 | 0.63 ± 0.02
Day 22 | 0.60 ± 0.00 | 0.60 ± 0.00 | 0.61 ± 0.01 | 0.59 ± 0.01 | 0.61 ± 0.01 | 0.60 ± 0.01
Week 14 | 0.80 ± 0.00 | 0.78 ± 0.01 | 0.78 ± 0.01 | 0.78 ± 0.01 | 0.79 ± 0.01 | 0.77 ± 0.02
Total protein (g/dL)
Day 3 | 5.5 ± 0.1 | 5.6 ± 0.1 | 5.5 ± 0.1 | 5.7 ± 0.1 | 5.8 ± 0.1* | 5.8 ± 0.1*
Day 22 | 6.3 ± 0.1 | 6.2 ± 0.1 | 6.3 ± 0.1 | 6.3 ± 0.1 | 6.3 ± 0.1 | 6.2 ± 0.1
Week 14 | 7.9 ± 0.1 | 7.9 ± 0.1 | 7.8 ± 0.1 | 7.6 ± 0.1 | 7.5 ± 0.1* | 7.3 ± 0.1**
Albumin (g/dL)
Day 3 | 3.6 ± 0.0 | 3.6 ± 0.0 | 3.5 ± 0.0 | 3.7 ± 0.0* | 3.7 ± 0.0* | 3.7 ± 0.1*
Day 22 | 3.8 ± 0.0 | 3.7 ± 0.0 | 3.8 ± 0.0 | 3.8 ± 0.0 | 3.8 ± 0.1 | 3.8 ± 0.0
Week 14 | 4.3 ± 0.0 | 4.3 ± 0.1 | 4.2 ± 0.1 | 4.1 ± 0.1* | 4.1 ± 0.1** | 4.0 ± 0.0**
Alanine aminotransferase (IU/L)
Day 3 | 72 ± 2 | 68 ± 2 | 65 ± 2* | 63 ± 2** | 63 ± 1** | 64 ± 2**
Day 22 | 61 ± 1 | 57 ± 2 | 59 ± 1 | 56 ± 2 | 55 ± 1* | 59 ± 2
Week 14 | 80 ± 7 | 96 ± 6 | 74 ± 5 | 83 ± 6 | 82 ± 6 | 71 ± 3
Alkaline phosphatase (IU/L)
Day 3 | 711 ± 12 | 742 ± 11 | 749 ± 17 | 760 ± 20 | 744 ± 15 | 818 ± 26**
Day 22 | 490 ± 13 | 488 ± 13 | 511 ± 13 | 538 ± 13 | 518 ± 12 | 586 ± 18**
Week 14 | 287 ± 6 | 298 ± 6 | 292 ± 11 | 315 ± 10 | 307 ± 9 | 333 ± 12**
Creatine kinase (IU/L)
Day 3 | 648 ± 77 | 360 ± 39* | 720 ± 121 | 504 ± 55 | 552 ± 90 | 420 ± 55
Day 22 | 252 ± 55 | 195 ± 31 | 223 ± 30 | 338 ± 127 | 207 ± 33 | 196 ± 26
Week 14 | 449 ± 97 | 276 ± 45 | 353 ± 57 | 414 ± 76 | 234 ± 35 | 302 ± 55
Sorbitol dehydrogenase (IU/L)
Day 3 | 34 ± 4 | 36 ± 2 | 34 ± 4 | 39 ± 2 | 39 ± 3 | 39 ± 3
Day 22 | 33 ± 3 | 31 ± 2 | 36 ± 2 | 29 ± 4 | 29 ± 2 | 28 ± 2
Week 14 | 64 ± 4 | 71 ± 3 | 69 ± 3 | 72 ± 2 | 66 ± 3 | 62 ± 2
Bile acids (µmol/L)
Day 3 | 40.9 ± 5.6 | 47.9 ± 6.8 | 47.5 ± 5.8 | 23.0 ± 3.0 | 32.7 ± 4.2 | 32.6 ± 6.6
Day 22 | 34.0 ± 5.2 | 42.6 ± 3.8 | 38.5 ± 3.9 | 27.1 ± 4.4 | 32.4 ± 1.6 | 32.1 ± 3.6
Week 14 | 27.9 ± 2.8 | 24.7 ± 3.0 | 33.5 ± 3.6 | 32.8 ± 2.8 | 36.0 ± 3.7 | 30.2 ± 4.3

* Significantly different (P ≤ 0.05) from the control group by Dunn’s or Shirley’s test.

** Significantly different (P ≤ 0.01) from the control group by Shirley’s test.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.

^b^ n = 9.

Table B-2 Hematology Data for Mice in the Three-month Feed Study of p-Toluenesulfonamide^a^

| 0 ppm | 625 ppm | 1,250 ppm | 2,500 ppm | 5,000 ppm | 10,000 ppm
Male
n | 10 | 10 | 9 | 10 | 10 | 9
Hematocrit (auto) (%) | 48.8 ± 0.9 | 46.0 ± 2.0 | 46.1 ± 2.4 | 49.5 ± 1.0 | 45.1 ± 2.2 | 50.8 ± 1.1
Manual hematocrit (%) | 51.5 ± 0.6 | 50.3 ± 0.6 | 50.8 ± 0.3 | 50.9 ± 0.5 | 50.7 ± 0.4 | 51.9 ± 0.8
Hemoglobin (g/dL) | 16.1 ± 0.3 | 15.1 ± 0.6 | 15.1 ± 0.8 | 16.2 ± 0.3 | 14.9 ± 0.8 | 16.7 ± 0.3
Erythrocytes (10^6^/µL) | 10.51 ± 0.21 | 9.89 ± 0.40 | 9.85 ± 0.48 | 10.59 ± 0.20 | 9.67 ± 0.46 | 10.87 ± 0.22
Erythrocyte distribution width (%) | 12.72 ± 0.08 | 12.75 ± 0.09 | 12.76 ± 0.08 | 12.71 ± 0.16 | 12.68 ± 0.08 | 12.30 ± 0.10*
Reticulocytes (10^3^/µL) | 277.90 ± 18.30 | 248.90 ± 15.80 | 277.30 ± 17.70 | 280.10 ± 11.80 | 274.20 ± 19.30 | 316.60 ± 24.60
Reticulocytes (%) | 2.63 ± 0.14 | 2.52 ± 0.13 | 2.81 ± 0.11 | 2.64 ± 0.09 | 2.83 ± 0.12 | 2.92 ± 0.23
Nucleated erythrocytes/100 leukocytes | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Mean cell volume (fL) | 46.7 ± 0.3 | 46.5 ± 0.2 | 46.7 ± 0.3 | 46.6 ± 0.2 | 46.4 ± 0.2 | 46.7 ± 0.3
Mean cell hemoglobin (pg) | 15.3 ± 0.0 | 15.3 ± 0.0 | 15.3 ± 0.1 | 15.3 ± 0.0 | 15.4 ± 0.1 | 15.4 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 33.0 ± 0.2 | 32.8 ± 0.1 | 32.8 ± 0.2 | 32.8 ± 0.1 | 33.0 ± 0.1 | 32.9 ± 0.1
Platelets (10^3^/µL) | 767.3 ± 27.1 | 772.0 ± 32.5 | 749.8 ± 24.8 | 769.0 ± 19.4 | 677.9 ± 28.8 | 704.6 ± 24.0
Mean platelet volume (μm^3^) | 5.770 ± 0.050 | 5.730 ± 0.045 | 5.844 ± 0.117 | 5.780 ± 0.103 | 5.890 ± 0.075 | 5.789 ± 0.099
Leukocytes (10^3^/µL) | 6.80 ± 0.31 | 6.44 ± 0.59 | 5.96 ± 0.67 | 5.74 ± 0.41 | 6.09 ± 0.47 | 5.91 ± 0.52
Segmented neutrophils (10^3^/µL) | 1.47 ± 0.09 | 1.45 ± 0.11 | 1.30 ± 0.15 | 1.23 ± 0.09 | 1.50 ± 0.22 | 1.25 ± 0.08
Bands (10^3^/µL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Metamyelocyte (10^3^/µL) | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Myelocyte (10^3^/µL) | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Lymphocytes (10^3^/µL) | 5.24 ± 0.24 | 4.90 ± 0.49 | 4.57 ± 0.51 | 4.43 ± 0.33 | 4.51 ± 0.34 | 4.59 ± 0.44
Atypical lymphocytes (10^3^/µL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Monocytes (10^3^/µL) | 0.06 ± 0.01 | 0.06 ± 0.01 | 0.06 ± 0.01 | 0.05 ± 0.01 | 0.05 ± 0.01 | 0.05 ± 0.01
Basophils (10^3^/µL) | 0.009 ± 0.002 | 0.013 ± 0.003 | 0.010 ± 0.002 | 0.010 ± 0.001 | 0.007 ± 0.002 | 0.003 ± 0.002
Eosinophils (10^3^/µL) | 0.03 ± 0.01 | 0.02 ± 0.01 | 0.02 ± 0.01 | 0.02 ± 0.01 | 0.01 ± 0.00 | 0.01 ± 0.00
Female
n | 10 | 9 | 8 | 9 | 9 | 8
Hematocrit (auto) (%) | 44.7 ± 1.4 | 47.2 ± 0.5 | 47.4 ± 0.6 | 47.9 ± 0.5 | 45.9 ± 1.5 | 46.8 ± 1.0
Manual hematocrit (%) | 50.6 ± 0.3 | 50.9 ± 0.4 | 50.8 ± 0.5 | 50.8 ± 0.4 | 51.0 ± 0.6 | 50.1 ± 0.7
Hemoglobin (g/dL) | 14.7 ± 0.4 | 15.7 ± 0.2 | 15.9 ± 0.2 | 15.9 ± 0.2 | 15.2 ± 0.5 | 15.6 ± 0.3
Erythrocytes (10^6^/µL) | 9.53 ± 0.28 | 9.97 ± 0.10 | 10.10 ± 0.15 | 10.11 ± 0.12 | 9.82 ± 0.30 | 9.95 ± 0.21
Erythrocyte distribution width (%) | 12.66 ± 0.09 | 12.80 ± 0.11 | 12.85 ± 0.12 | 12.53 ± 0.19 | 12.52 ± 0.11 | 12.76 ± 0.14
Reticulocytes (10^3^/µL) | 268.40 ± 15.30 | 267.20 ± 12.00 | 275.60 ± 23.60 | 263.70 ± 16.70 | 255.70 ± 13.70 | 259.60 ± 14.70
Reticulocytes (%) | 2.82 ± 0.15 | 2.68 ± 0.12 | 2.73 ± 0.22 | 2.60 ± 0.15 | 2.61 ± 0.14 | 2.63 ± 0.17
Nucleated erythrocytes/100 leukocytes | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Mean cell volume (fL) | 47.0 ± 0.2 | 47.3 ± 0.3 | 46.9 ± 0.3 | 47.2 ± 0.2 | 46.8 ± 0.1 | 47.0 ± 0.0
Mean cell hemoglobin (pg) | 15.5 ± 0.1 | 15.7 ± 0.1 | 15.8 ± 0.1 | 15.8 ± 0.1 | 15.5 ± 0.1 | 15.7 ± 0.1
Mean cell hemoglobin concentration (g/dL) | 33.0 ± 0.1 | 33.2 ± 0.1 | 33.6 ± 0.2 | 33.3 ± 0.2 | 33.2 ± 0.1 | 33.4 ± 0.2
Platelets (10^3^/µL) | 667.2 ± 23.3 | 688.0 ± 18.3 | 699.4 ± 42.4 | 656.8 ± 25.9 | 645.0 ± 24.6 | 612.1 ± 25.4
Mean platelet volume (μm^3^) | 5.430 ± 0.303 | 5.800 ± 0.109 | 5.863 ± 0.105 | 5.700 ± 0.094 | 5.622 ± 0.106 | 5.763 ± 0.112
Leukocytes (10^3^/µL) | 4.65 ± 0.35 | 4.11 ± 0.26 | 4.79 ± 0.31 | 3.73 ± 0.23 | 4.52 ± 0.42 | 4.96 ± 0.51
Segmented neutrophils (10^3^/µL) | 1.10 ± 0.05 | 1.03 ± 0.06 | 1.21 ± 0.12 | 0.84 ± 0.07 | 1.04 ± 0.09 | 1.24 ± 0.13
Bands (10^3^/µL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Metamyelocyte (10^3^/µL) | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Myelocyte (10^3^/µL) | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000 | 0.000 ± 0.000
Lymphocytes (10^3^/µL) | 3.50 ± 0.31 | 3.03 ± 0.22 | 3.50 ± 0.23 | 2.85 ± 0.17 | 3.43 ± 0.34 | 3.66 ± 0.37
Atypical lymphocytes (10^3^/µL) | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00 | 0.00 ± 0.00
Monocytes (10^3^/µL) | 0.03 ± 0.00 | 0.03 ± 0.00 | 0.04 ± 0.01 | 0.03 ± 0.00 | 0.03 ± 0.01 | 0.04 ± 0.01
Basophils (10^3^/µL) | 0.006 ± 0.002 | 0.004 ± 0.002 | 0.008 ± 0.003 | 0.004 ± 0.002 | 0.004 ± 0.002 | 0.010 ± 0.002
Eosinophils (10^3^/µL) | 0.01 ± 0.00 | 0.01 ± 0.01 | 0.03 ± 0.01 | 0.02 ± 0.00 | 0.02 ± 0.01 | 0.02 ± 0.01

* Significantly different (P ≤ 0.05) from the control group by Dunn’s test.

^a^ Data are presented as mean ± standard error. Statistical tests were performed on unrounded data.