# Appendix A Summary of Nonneoplastic Lesions in F344/NTAC Rats and Mice

Table A-1 Summary of the Incidence of Nonneoplastic Lesions in Male Rats in the Three-month Feed Study of p-Toluenesulfonamide

| 0 ppm | 625 ppm | 1,250 ppm | 2,500 ppm | 5,000 ppm | 10,000 ppm
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Survivors
Terminal euthanasia | 10 | 10 | 10 | 10 | 10 | 10
Animals examined microscopically | 10 | – | – | – | – | 10
Alimentary System
Esophagus^a^ | (10) | – | – | – | – | (10)
Intestine large, cecum | (10) | – | – | – | – | (10)
Intestine large, colon | (10) | – | – | – | – | (10)
Intestine large, rectum | (10) | – | – | – | – | (10)
Intestine small, duodenum | (10) | – | – | – | – | (10)
Intestine small, ileum | (10) | – | – | – | – | (10)
Intestine small, jejunum | (10) | – | – | – | – | (10)
Liver | (10) | – | – | – | – | (10)
Inflammation, chronic^b^ | 9 (1.0)^c^ | – | – | – | – | 9 (1.0)
Pancreas | (10) | – | – | – | – | (10)
Salivary glands | (10) | – | – | – | – | (10)
Stomach, forestomach | (10) | – | – | – | – | (10)
Stomach, glandular | (10) | – | – | – | – | (10)
Glands, ectasia, focal | 1 (1.0) | – | – | – | – | 1 (1.0)
Tongue | (10) | – | – | – | – | (10)
Cardiovascular System
Blood vessel | (10) | – | – | – | – | (10)
Heart | (10) | – | – | – | – | (10)
Cardiomyopathy | 4 (1.0) | – | – | – | – | 4 (1.0)
Infiltration cellular, histiocyte, focal | 2 (1.0) | – | – | – | – | 1 (1.0)
Endocrine System
Adrenal cortex | (10) | – | – | – | – | (10)
Adrenal medulla | (10) | – | – | – | – | (10)
Parathyroid gland | (10) | – | – | – | – | (9)
Pituitary gland | (10) | – | – | – | – | (10)
Thyroid gland | (10) | – | – | – | – | (10)
General Body System
None | – | – | – | – | – | –
Genital System
Epididymis | (10) | – | – | – | – | (10)
Preputial gland | (9) | – | – | – | – | (10)
Inflammation, chronic | 2 (1.0) | – | – | – | – | –
Prostate | (10) | – | – | – | – | (10)
Seminal vesicle | (10) | – | – | – | – | (10)
Testes | (10) | – | – | – | – | (10)
Atrophy | – | – | – | – | – | 1 (2.0)
Metaplasia, cartilagenous, focal | – | – | – | – | – | 1 (1.0)
Hematopoietic System
Bone marrow | (10) | – | – | – | – | (10)
Lymph node, mandibular | (10) | – | – | – | – | (10)
Lymph node, mesenteric | (10) | – | – | – | – | (10)
Infiltration cellular, histiocyte | – | – | – | – | – | 1 (3.0)
Spleen | (10) | – | – | – | – | (10)
Thymus | (10) | – | – | – | – | (10)
Integumentary System
Mammary gland | (7) | – | – | – | – | (9)
Skin | (10) | – | – | – | – | (10)
Musculoskeletal System
Bone | (10) | – | – | – | – | (10)
Nervous System
Brain | (10) | – | – | – | – | (10)
Respiratory System
Lung | (10) | – | – | – | – | (10)
Hemorrhage | 1 (1.0) | – | – | – | – | 2 (1.0)
Infiltration cellular, histiocyte | 1 (1.0) | – | – | – | – | 2 (1.0)
Inflammation, chronic active | 2 (1.0) | – | – | – | – | 3 (1.7)
Nose | (10) | – | – | – | – | (10)
Pleura | (1) | – | – | – | – | –
Trachea | (10) | – | – | – | – | (10)
Special Senses System
Eye | (10) | – | – | – | – | (10)
Harderian gland | (10) | – | – | – | – | (10)
Urinary System
Kidney | (10) | – | – | – | – | (10)
Inflammation | 1 (1.0) | – | – | – | – | –
Nephropathy | 4 (1.3) | – | – | – | – | 4 (1.0)
Urinary bladder | (10) | – | – | – | – | (10)

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Table A-2 Summary of the Incidence of Nonneoplastic Lesions in Female Rats in the Three-month Feed Study of p-Toluenesulfonamide

| 0 ppm | 625 ppm | 1,250 ppm | 2,500 ppm | 5,000 ppm | 10,000 ppm
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Survivors
Terminal euthanasia | 10 | 10 | 10 | 10 | 10 | 10
Animals examined microscopically | 10 | – | – | – | – | 10
Alimentary System
Esophagus^a^ | (10) | – | – | – | – | (10)
Intestine large, cecum | (10) | – | – | – | – | (10)
Intestine large, colon | (10) | – | – | – | – | (10)
Intestine large, rectum | (10) | – | – | – | – | (10)
Intestine small, duodenum | (10) | – | – | – | – | (10)
Intestine small, ileum | (10) | – | – | – | – | (10)
Intestine small, jejunum | (10) | – | – | – | – | (10)
Liver | (10) | – | – | – | – | (10)
Hepatodiaphragmatic nodule^b^ | – | – | – | – | – | 1
Inflammation, chronic | 10 (1.2)^c^ | – | – | – | – | 9 (1.0)
Pancreas | (10) | – | – | – | – | (10)
Inflammation, chronic | – | – | – | – | – | 1 (1.0)
Acinus, atrophy | 1 (1.0) | – | – | – | – | 1 (1.0)
Salivary glands | (10) | – | – | – | – | (10)
Stomach, forestomach | (10) | – | – | – | – | (10)
Stomach, glandular | (10) | – | – | – | – | (10)
Hyperplasia, basal cell | 1 (1.0) | – | – | – | – | –
Tongue | (10) | – | – | – | – | (10)
Cardiovascular System
Blood vessel | (10) | – | – | – | – | (10)
Heart | (10) | – | – | – | – | (10)
Cardiomyopathy | 2 (1.0) | – | – | – | – | 1 (1.0)
Endocrine System
Adrenal cortex | (10) | – | – | – | – | (10)
Adrenal medulla | (10) | – | – | – | – | (10)
Parathyroid gland | (10) | – | – | – | – | (9)
Pituitary gland | (10) | – | – | – | – | (10)
Thyroid gland | (10) | – | – | – | – | (10)
General Body System
None | – | – | – | – | – | –
Genital System
Clitoral gland | (10) | – | – | – | – | (10)
Inflammation, chronic | 1 (1.0) | – | – | – | – | –
Ovary | (10) | – | – | – | – | (10)
Cyst, focal | 1 (3.0) | – | – | – | – | –
Uterus | (10) | – | – | – | – | (10)
Bilateral, hydrometra | 2 (2.0) | – | – | – | – | –
Hematopoietic System
Bone marrow | (10) | – | – | – | – | (10)
Lymph node, mandibular | (10) | – | – | – | – | (10)
Lymph node, mesenteric | (10) | – | – | – | – | (10)
Spleen | (10) | – | – | – | – | (10)
Ectopic tissue | 1 | – | – | – | – | –
Thymus | (10) | – | – | – | – | (10)
Integumentary System
Mammary gland | (10) | – | – | – | – | (10)
Skin | (10) | – | – | – | – | (10)
Musculoskeletal System
Bone | (10) | – | – | – | – | (10)
Nervous System
Brain | (10) | – | – | – | – | (10)
Respiratory System
Lung | (10) | – | – | – | – | (10)
Infiltration cellular, histiocyte | 1 (1.0) | – | – | – | – | 1 (1.0)
Inflammation, chronic active | 1 (1.0) | – | – | – | – | 1 (2.0)
Nose | (10) | – | – | – | – | (10)
Trachea | (10) | – | – | – | – | (10)
Special Senses System
Eye | (10) | – | – | – | – | (10)
Harderian gland | (10) | – | – | – | – | (10)
Inflammation, chronic | 1 (2.0) | – | – | – | – | 1 (1.0)
Urinary System
Kidney | (10) | – | – | – | – | (10)
Nephropathy | 1 (1.0) | – | – | – | – | –
Pelvis, dilatation, focal | 1 (2.0) | – | – | – | – | –
Urinary bladder | (10) | – | – | – | – | (10)

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Table A-3 Summary of the Incidence of Nonneoplastic Lesions in Male Mice in the Three-month Feed Study of p-Toluenesulfonamide

| 0 ppm | 625 ppm | 1,250 ppm | 2,500 ppm | 5,000 ppm | 10,000 ppm
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Survivors
Terminal euthanasia | 10 | 10 | 10 | 10 | 10 | 10
Animals examined microscopically | 10 | – | – | – | – | 10
Alimentary System
Esophagus^a^ | (10) | – | – | – | – | (10)
Gallbladder | (9) | – | – | – | – | (10)
Intestine large, cecum | (10) | – | – | – | – | (10)
Intestine large, colon | (10) | – | – | – | – | (10)
Intestine large, rectum | (10) | – | – | – | – | (10)
Intestine small, duodenum | (10) | – | – | – | – | (10)
Intestine small, ileum | (10) | – | – | – | – | (10)
Intestine small, jejunum | (10) | – | – | – | – | (10)
Liver | (10) | – | – | – | – | (10)
Inflammation, chronic^b^ | 3 (1.0)^c^ | – | – | – | – | 3 (1.0)
Oral mucosa | (10) | – | – | – | – | (10)
Pancreas | (10) | – | – | – | – | (10)
Salivary glands | (10) | – | – | – | – | (10)
Stomach, forestomach | (10) | – | – | – | – | (10)
Stomach, glandular | (10) | – | – | – | – | (10)
Tongue | (10) | – | – | – | – | (10)
Cardiovascular System
Blood vessel | (9) | – | – | – | – | (10)
Heart | (10) | – | – | – | – | (10)
Endocrine System
Adrenal cortex | (10) | – | – | – | – | (10)
Subcapsular, hyperplasia | 1 (1.0) | – | – | – | –
Adrenal medulla | (10) | – | – | – | – | (10)
Parathyroid gland | (5) | – | – | – | – | (9)
Pituitary gland | (10) | – | – | – | – | (10)
Thyroid gland | (10) | – | – | – | – | (10)
Cyst | 1 | – | – | – | –
General Body System
None | – | – | – | – | – | –
Genital System
Epididymis | (10) | – | – | – | – | (10)
Preputial gland | (10) | – | – | – | – | (10)
Prostate | (10) | – | – | – | – | (10)
Seminal vesicle | (10) | – | – | – | – | (10)
Testes | (10) | – | – | – | – | (10)
Hematopoietic System
Bone marrow | (10) | – | – | – | – | (10)
Lymph node, mandibular | (10) | – | – | – | – | (10)
Lymph node, mesenteric | (10) | – | – | – | – | (10)
Spleen | (10) | – | – | – | – | (10)
Thymus | (10) | – | – | – | – | (10)
Integumentary System
Mammary gland | (4) | – | – | – | – | (5)
Skin | (10) | – | – | – | – | (10)
Musculoskeletal System
Bone | (10) | – | – | – | – | (10)
Nervous System
Brain | (10) | – | – | – | – | (10)
Respiratory System
Larynx | (10) | – | – | – | – | (10)
Lung | (10) | – | – | – | – | (10)
Nose | (10) | – | – | – | – | (10)
Trachea | (10) | – | – | – | – | (10)
Special Senses System
Eye | (10) | – | – | – | – | (10)
Retrobulbar, inflammation, suppurative | 3 (1.3) | – | – | – | – | 5 (1.4)
Harderian gland | (10) | – | – | – | – | (10)
Inflammation, suppurative | 1 (2.0) | – | – | – | – | 1 (2.0)
Urinary System
Kidney | (10) | – | – | – | – | (10)
Inflammation, chronic | 2 (1.0) | – | – | – | – | –
Nephropathy | 1 (1.0) | – | – | – | – | –
Urinary bladder | (10) | – | – | – | – | (10)

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Table A-4 Summary of the Incidence of Nonneoplastic Lesions in Female Mice in the Three-month Feed Study of p-Toluenesulfonamide

| 0 ppm | 625 ppm | 1,250 ppm | 2,500 ppm | 5,000 ppm | 10,000 ppm
Disposition Summary
Animals initially in study | 10 | 10 | 10 | 10 | 10 | 10
Early deaths
Accidental death | – | – | – | – | – | 1
Survivors
Terminal euthanasia | 10 | 10 | 10 | 10 | 10 | 9
Animals examined microscopically | 10 | – | – | – | – | 10
Alimentary System
Esophagus^a^ | (10) | – | – | – | – | (10)
Gallbladder | (10) | – | – | – | – | (9)
Intestine large, cecum | (10) | – | – | – | – | (9)
Intestine large, colon | (10) | – | – | – | – | (9)
Intestine large, rectum | (10) | – | – | – | – | (9)
Intestine small, duodenum | (10) | – | – | – | – | (9)
Intestine small, ileum | (10) | – | – | – | – | (9)
Intestine small, jejunum | (10) | – | – | – | – | (9)
Liver | (10) | – | – | – | – | (9)
Inflammation, chronic^b^ | 2 (1.0)^c^ | – | – | – | – | 4 (1.0)
Necrosis | 1(1.0) | – | – | – | – | –
Oral mucosa | (10) | – | – | – | – | (10)
Pancreas | (10) | – | – | – | – | (9)
Salivary glands | (10) | – | – | – | – | (10)
Stomach, forestomach | (10) | – | – | – | – | (9)
Stomach, glandular | (10) | – | – | – | – | (9)
Tongue | (10) | – | – | – | – | (10)
Cardiovascular System
Blood vessel | (10) | – | – | – | – | (10)
Heart | (10) | – | – | – | – | (10)
Endocrine System
Adrenal cortex | (10) | – | – | – | – | (10)
Subcapsular, hyperplasia | 5 (1.8) | – | – | – | – | 6 (1.8)
Adrenal medulla | (10) | – | – | – | – | (10)
Parathyroid gland | (10) | – | – | – | – | (10)
Pituitary gland | (10) | – | – | – | – | (10)
Thyroid gland | (10) | – | – | – | – | (10)
General Body System
None | – | – | – | – | – | –
Genital System
Clitoral gland | (1) | – | – | – | – | (1)
Ovary | (10) | – | – | – | – | (9)
Inflammation, granulomatous, focal | – | – | – | – | – | 1 (2.0)
Uterus | (10) | – | – | – | – | (9)
Hematopoietic System
Bone marrow | (10) | – | – | – | – | (10)
Lymph node, mandibular | (10) | – | – | – | – | (10)
Lymph node, mesenteric | (10) | – | – | – | – | (8)
Spleen | (10) | – | – | – | – | (9)
Thymus | (10) | – | – | – | – | (10)
Integumentary System
Mammary gland | (10) | – | – | – | – | (10)
Skin | (10) | – | – | – | – | (10)
Musculoskeletal System
Bone | (10) | – | – | – | – | (10)
Nervous System
Brain | (10) | – | – | – | – | (10)
Respiratory System
Larynx | (10) | – | – | – | – | (10)
Lung | (10) | – | – | – | – | (10)
Hemorrhage | 1 (3.0) | – | – | – | – | –
Arteriole, inflammation, focal, acute | – | – | – | – | – | 1 (2.0)
Nose | (10) | – | – | – | – | (10)
Trachea | (10) | – | – | – | – | (10)
Special Senses System
Eye | (10) | – | – | – | – | (10)
Retina, dysplasia | – | – | – | – | – | 1 (2.0)
Retrobulbar, inflammation, suppurative | 1 (1.0) | – | – | – | – | 1 (2.0)
Harderian gland | (10) | – | – | – | – | (10)
Inflammation, suppurative | – | – | – | – | – | 1 (2.0)
Inflammation, chronic | – | – | – | – | – | 1 (1.0)
Urinary System
Kidney | (10) | – | – | – | – | (10)
Nephropathy | 2 (1.0) | – | – | – | – | –
Urinary bladder | (10) | – | – | – | – | (9)
Inflammation, chronic active | – | – | – | – | – | 1 (3.0)

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.