# Preface

The National Toxicology Program’s (NTP’s) Nanotechnology Safety Initiative was instituted in 2004 due to the widespread use of nanoscale materials and inadequate information on possible biological interactions and toxicity following exposure. This initiative is a broad-based research program with the goal of addressing potential human health hazards associated with the manufacture and use of nanoscale materials and is driven by the current and anticipated future research and development focus on nanotechnology. The research program was designed to comprehensively evaluate the toxicological properties of major nanoscale materials classes, which represent a cross-section of composition, size, surface coatings, and physiochemical properties. Nanoscale materials evaluated under this initiative include: (1) metal oxides (titanium dioxide and zinc oxide), (2) fluorescent crystalline semiconductors (quantum dots; cadmium selenide/zinc sulfite spheres), (3) carbon-based fullerenes, (4) carbon nanotubes, (5) nanoscale silver, and (6) nanoscale gold. Further information about the NTP Nanotechnology Safety Initiative is available at: https://ntp.niehs.nih.gov/whatwestudy/topics/nano/index.html.