# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2378-8992

DOI: https://doi.org/10.22427/NTP-TOX-87

Report Series: NTP Toxicity Report Series

Report Series Number: 87

Official citation: National Toxicology Program (NTP). 2020. NTP technical report on the toxicity studies of fullerene C_60_ (1 µm and 50 nm) (CASRN 99685-96-8) administered by nose-only inhalation to Wistar Han [Crl:WI (Han)] rats and B6C3F1/N mice. Research Triangle Park, NC: National Toxicology Program. Toxicity Report 87.