# Peer Review

The draft NTP Technical Report on the Toxicity Studies of Fullerene C_60_ (1 µm and 50 nm) (CASRN 99685-96-8) Administered by Nose-only Inhalation to Wistar Han [Crl:WI (Han)] Rats and B6C3F1/N Mice was evaluated by the reviewers listed below. These reviewers served as independent scientists, not as representatives of any institution, company, or governmental agency. In this capacity, reviewers determined if the design and conditions of these NTP studies were appropriate and ensured that this Toxicity Study Report presents the experimental results and conclusions fully and clearly.

- Alison Elder, Ph.D.
  Department of Environmental Medicine, University of Rochester
  Rochester, New York, USA
- Clark Lantz, Ph.D.
  Professor, Cellular and Molecular Medicine, University of Arizona
  Tucson, Arizona, USA