# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  D.L. Morgan, Ph.D., Co-Study Scientist (retired)
  N.J. Walker, Ph.D. Co-Study Scientist
  M.F. Cesta, D.V.M., Ph.D., Study Pathologist
  C.R. Blystone, M.S., Ph.D.
  P.M. Foster, Ph.D. (retired)
  D.R. Germolec, Ph.D.
  R.A. Herbert, D.V.M., Ph.D.
  M.J. Hooth, Ph.D.
  A.P. King-Herbert, D.V.M.
  G.E. Kissling, Ph.D. (retired)
  B.S. McIntyre, Ph.D.
  D.E. Malarkey, D.V.M., Ph.D.
  J.H. Roycroft, Ph.D. (retired)
  B.C. Sayers, Ph.D.
  K.A. Shipkowski, Ph.D.
  K.R. Shockley, Ph.D.
  S.L. Smith-Roe, Ph.D.
  M.D. Stout, Ph.D.
  G.S. Travlos, D.V.M.
  M.K. Vallant, B.S., MT (retired)
  S. Waidyanatha, Ph.D.
  K.L. Witt, M.S.
- Battelle Columbus Operations, Columbus, Ohio, USA
  Conducted studies and evaluated pathology findings
  J.A. Dill, Ph.D., Principal Investigator
  G.L. Baker, Ph.D.
  A. Gupta, M.S.
  B.K. Hayden
  S.L. Grumbein, D.V.M., Ph.D.
  L.M. Staska, D.V.M., Ph.D.
- ILS, Inc., Research Triangle Park, North Carolina, USA
  Evaluated and interpreted results and reported findings
  M.H. Boyle, D.V.M.
- Virginia Commonwealth University, Richmond, Virginia, USA
  Conducted immunotoxicity studies
  K.L. White, Jr., Ph.D., Principal Investigator
  M.J. Smith, Ph.D.
- Experimental Pathology Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Provided pathology review
  M.H. Hamlin, II, D.V.M., Ph.D., Principal Investigator
  A.E. Brix, D.V.M., Ph. D.
- Pathology Associates, A Division of Charles River Laboratories, Inc., Research Triangle Park, North Carolina, USA
  Coordinated NTP Pathology Peer Review of the 3-month rats and mice (November 16, 2009)
  W.G. Lieuallen, D.V.M., Ph.D.
- RTI International, Research Triangle Park, North Carolina, USA
  Provided SMVCE analysis
  R.W. Tyl, Ph.D., Principal Investigator
  B.T. Hamby, B.S.
  C.S. Sloan, M.S.