# References

1 Hirsch A The era of carbon allotropes. Nat Mater. 2010;9(11):868–871. 10.1038/nmat2885 20966925
2 Kroto HW Allaf AW Balm SP C60: buckminsterfullerene. Chem Rev. 1991;91:1213–1235.10.1021/cr00006a005
3 Terrones H Mackay AL The geometry of hypothetical curved graphite structures. Carbon. 1992;30:1251–1260.10.1016/0008-6223(92)90066-6
4 National Center for Biotechnology Information (NCBI). PubChem Open Chemistry Database. CID = 123591, Fullerene C60. Bethesda, MD: National Institutes of Health, National Library of Medicine; 2017. https://pubchem.ncbi.nlm.nih.gov/compound/123591#Section=Top
5 Sigma Aldrich. Safety Data Sheet: Fullerene-C60, Product Number 379646. 2017.https://www.sigmaaldrich.com/Graphics/COfAInfo/SigmaSAPQM/SPEC/57/572500/572500-BULK_______ALDRICH__.pdf
6 Johnston HJ Hutchinson GR Christensen FM Aschberger K Stone V The biological mechanisms and physiochemical characteristics responsible for driving fullerene toxicity. Toxicol Sci. 2010;114(2):162–182. 10.1093/toxsci/kfp265 19901017
7 Bleeker EAJ, de Jong WH, Geertsma RE, Groenewold M, Heugens EHW, Koers-Jacquemijns M, van de Meent D, Popma JR, Rietveld AG, Wijnhoven SWP, et al. Considerations on the EU definition of a nanomaterial: Science to support policy making. Regul Toxicol Pharm. 2013; 65:119-125. 10.1016/j.yrtph.2012.11.007
8 European Commission Commission recommendation of 18 October 2011 on the definition of nanomaterial (2011/696/EU). Off J. Eur Union. 2011;L275:38–40.
9 Fortner JD Lyon DY Sayes CM Boyd AM Falkner JC Hotze EM Alemany LB Tao YJ Guo W Ausman KD C60 in water: nanocrystal formation and microbial response. Environ Sci Technol. 2005;39(11):4307–4316. 10.1021/es048099n 15984814
10 Materials Electrochemical Research Corporation MER fullerene products. 2017. http://www.mercorp.com/fullbro.pdf
11 Baker GL Gupta A Clark ML Valenzuela BR Staska LM Harbo SJ Pierce JT Dill JA Inhalation toxicity and lung toxicokinetics of C60 fullerene nanoparticles and microparticles. Toxicol Sci. 2008;101(1):122–131. 10.1093/toxsci/kfm243 17878152
12 Deguchi S Alargova RG Tsujii K Stable dispersions of fullerenes, C60 and C70, in water. Preparation and characterization. Langmuir. 2001;17:6013–6017.10.1021/la010651o
13 Gharbi N Pressac M Hadchouel M Szwarc H Wilson SR Moussa F [60]Fullerene is a powerful antioxidant in vivo with no acute or subacute toxicity. Nano Lett. 2005;5(12):2578–2585. 10.1021/nl051866b 16351219
14 Scott LT Boorum MM McMahon BJ Hagen S Mack J Blank J Wegner H de Meijere A A rational chemical synthesis of C60. Science. 2002;295(5559):1500–1503. 10.1126/science.1068427 11859187
15 Hendren CO Mesnard X Dröge J Wiesner MR Estimating production data for five engineered nanomaterials as a basis for exposure assessment. Environ Sci Technol. 2011;45(7):2562–2569. 10.1021/es103300g 21391627
16 Murr LE Esquivel EV Bang JJ de la Rosa G Gardea-Torresdey JL Chemistry and nanoparticulate compositions of a 10,000 year-old ice core melt water. Water Res. 2004;38(19):4282–4296. 10.1016/j.watres.2004.08.010 15491674
17 Wang Z Xuepeng L Wenmin W Xunjiang X Tang ZC Huang RB Zheng LS Fullerenes in the fossil of dinosaur egg. Fuller Sci Technol. 1998;6:715–720.10.1080/10641229809350232
18 Food and Drug Administration (FDA) Guidance for industry: Safety of nanomaterials in cosmetic products. United States Department of Health and Human Services, Food and Drug Administration. Center for Food Safety and Applied Nutrition; 2014.
19 Gwinn MR Vallyathan V Nanoparticles: health effects – pros and cons. Environ Health Perspect. 2006;114(12):1818–1825. 10.1289/ehp.8871 17185269
20 Nel A Xia T Mädler L Li N Toxic potential of materials at the nanolevel. Science. 2006;311(5761):622–627. 10.1126/science.1114397 16456071
21 Bonner JC Nanoparticles as a potential cause of pleural and interstitial lung disease. Proc Am Thorac Soc. 2010;7(2):138–141. 10.1513/pats.200907-061RM 20427587
22 Lockman PR Koziara JM Mumper RJ Allen DD Nanoparticle surface charges alter blood brain barrier integrity and permeability. J Drug Target. 2008;12(9-10):635–641. 10.1080/10611860400015936 15621689
23 Halford B Fullerene for the face. Chem Eng News. 2006;84:47.10.1021/cen-v084n013.p047
24 Singh R Lillard JW Jr Nanoparticle-based targeted drug delivery. Exp Mol Pathol. 2009;86(3):215–223. 10.1016/j.yexmp.2008.12.004 19186176
25 Benn TM Westorhoff P Herckes P Detection of fullerene (C60 and C70) in commercial cosmetics. Environ Pollut. 2011;159(5):1334–1342. 10.1016/j.envpol.2011.01.018 21300421
26 Kato S Taira H Aoshima H Saitoh Y Miwa N Clinical evaluation of fullerene-C60 dissolved in squalene for anti-wrinkle cosmetics. J Nanosci Nanotechnol. 2010;10(10):6769–6774. 10.1166/jnn.2010.3053 21137794
27 Fujita K Morimoto Y Ogami A Myojyo T Tanaka I Shimada M Wang WN Endoh S Uchida K Nakazato T Gene expression profiles in rat lung after inhalation exposure to C60 fullerene particles. Toxicology. 2009;258(1):47–55. 10.1016/j.tox.2009.01.005 19167457
28 Oberdörster G Oberdörster E Oberdörster J Nanotechnology: an emerging discipline evolving from studies of ultrafine particles. Environ Health Perspect. 2005;113(7):823–838. 10.1289/ehp.7339 16002369
29 Utsunomiya S Jensen KA Keeler GJ Ewing RC Uraninite and fullerene in atmospheric particulates. Environ Sci Technol. 2002;36(23):4943–4947. 10.1021/es025872a 12523404
30 Mercer RR Scabilloni J Wang L Kisin E Murray AR Schwegler-Berry D Shvedova AA Castranova V Alteration of deposition pattern and pulmonary response as a result of improved dispersion of aspirated single-walled carbon nanotubes in a mouse model. Am J Physiol Lung Cell Mol Physiol. 2008;294(1):L87–L97. 10.1152/ajplung.00186.2007 18024722
31 Oberdörster G Ferin J Lehnert BE Correlation between particle size, in vivo particle persistence, and lung injury. Environ Health Perspect. 1994;102 Suppl 5:173–179. 7882925
32 Oberdörster G Ferin J Gelein R Soderholm SC Finkelstein J Role of the alveolar macrophage in lung injury: studies with ultra-fine particles. Environ Health Perspect. 1992;97:193–199. 1396458
33 Ferin J Oberdörster G Penney DP Soderholm SC Glein RPHC Increased pulmonary toxicity of ultrafine particles? I. Particle clearance, translocation, and morphology. J Aerosol Sci. 1990;21:381–384.10.1016/0021-8502(90)90064-5
34 Harmsen AG Muggenburg BA Snipes MB Bice DE The role of macrophages in parcile translocation from lungs to lymph nodes. Science. 1985;230(4731):1277–1280. 10.1126/science.4071052 4071052
35 Mercer RR Scabilloni JF Hubbs AF Wang L Battelli L McKinney W Castronova V Porter DW Extrapulmonary transport of MWCNT following inhalation exposure. Part Fibre Toxicol. 2013;10:38–51. 10.1186/1743-8977-10-38 23927530
36 Shipkowski KA Sanders JM McDonald JD Walker NJ Waidyanatha S Disposition of fullerene C60 in rats following intratracheal or intravenous administration. Xenobiotica. 2019;49(9):1078–1085. 10.1080/00498254.2018.1528646 30257131
37 Ema M Kobayashi N Naya M Hanai S Nakanishi J Reproductive and developmental toxicity studies of manufactured nanomaterials. Reprod Toxicol. 2010;30(3):343–352. 10.1016/j.reprotox.2010.06.002 20600821
38 Sumner SC Fennell TR Snyder RW Taylor GF Lewin AH Distribution of carbon-14 labeled C60 ([14C]C60) in the pregnant and in the lactating dam and the effect of C60 exposure on the biochemical profile of urine. J Appl Toxicol. 2010;30(4):354–360. 20063269
39 Park EJ Kim H Kim Y Yi J Choi K Park K Carbon fullerenes (C60s) can induce inflammatory responses in the lung of mice. Toxicol Appl Pharmacol. 2010;244(2):226–233. 10.1016/j.taap.2009.12.036 20064541
40 Sayes CM Marchione AA Reed KL Warheit DB Comparative pulmonary toxicity assessments of C60 water suspensions in rats: few differences in fullerene toxicity in vivo in contrast to in vitro profiles. Nano Lett. 2007;7(8):2399–2406. 10.1021/nl0710710 17630811
41 Roursgaard M Poulsen SS Kepley CL Hammer M Nielsen GD Larsen ST Polyhydroxylated C60 fullerene (fullerenol) attenuates neutrophilic lung inflammation in mice. Basic Clin Pharmacol Toxicol. 2008;103(4):386–388. 10.1111/j.1742-7843.2008.00315.x 18793270
42 Chen HHC Yu C Ueng TH Chen S Chen BJ Huang KJ Chiang LY Acute and subacute toxicity study of water-soluble polyalkylsulfonated C60 in rats. Toxicol Pathol. 1998;26(1):143–151. 10.1177/019262339802600117 9502397
43 Moussa F Trivin F Céolin R Hadchouel M Sizarert PY Greungny V Fabre C Rassat A Szwarc H Early effects of C60 administration in Swiss mice: A preliminary account for in vivo C60 toxicity. Fuller Sci Technol. 1996;4:21–29.10.1080/10641229608001534
44 Mori T Takada H Ito S Matsubayashi K Miwa N Sawaguchi T Preclinical studies on safety of fullerene upon acute oral administration and evaluation for no mutagenesis. Toxicology. 2006;225(1):48–54. 10.1016/j.tox.2006.05.001 16782258
45 Baati T Bourasset F Gharbi N Njim L Abderrabba M Kerkeni A Szwarc H Moussa F The prolongation of the lifespan of rats by repeated oral administration of [60] fullerene. Biomaterials. 2012;33(19):4936–4946. 10.1016/j.biomaterials.2012.03.036 22498298
46 Patri A Dobrovolskaia MA Stern ST McNeil SE Preclinical characterization of engineered nanoparticles intended for cancer therapeutics. Nanotechnology for Cancer Therapy. Boca Raton (FL): CRC Press, Taylor & Francis Group; 2007. p. 105–137.
47 Smith MJ McLoughlin CE White KL Jr Germolec DR Evaluating the adverse effects of nanomaterials on the immune system with animal models. In: Dobrovolskaia MA McNeil SEeditors. Handbook of Immunological Properties of Engineered Nanomaterials. Hackensack (NJ): World Scientific Publishing Co.; 2013. p. 639–670.10.1142/9789814390262_0020
48 Yamashita K Sakai M Takemoto N Tsukimoto M Uchida K Yajima H Oshio S Takeda K Kojima S Attenuation of delayed-type hypersensitivity by fullerene treatment. Toxicology. 2009;261(1-2):19–24. 10.1016/j.tox.2009.04.034 19376187
49 Zogovic NS Nikolic NS Vranjes-Djuric SD Harhaji LM Vucicevic LM Janjetovic KD Misirkic MS Todorovic-Markovic BM Markovic ZM Milonjic SK Opposite effect of nanocrystalline fullerene (C60) on tumour cell growth in vitro and in vivo and a possible role of immunosuppression in the cancer-promoting activity of C60. Biomaterials. 2009;30(36):6940–6946. 10.1016/j.biomaterials.2009.09.007 19781768
50 Chen BX Wilson SR Das M Coughlin DJ Erlanger BF Antigenicity of fullerenes: antibodies specific for fullerenes and their characteristics. Proc Natl Acad Sci USA. 1998;95(18):10,809–810, 813. https://www.pnas.org/content/95/18/10809.long. 10.1073/pnas.95.18.10809 9724786
51 Tsuchiya T Oguri I Yamakoshi YN Miyata N Novel harmful effects of [60]fullerene on mouse embryos in vitro and in vivo. FEBS Lett. 1996;393(1):139–145. 10.1016/0014-5793(96)00812-5 8804443
52 Zhu X Zhu L Li Y Duan Z Chen W Alvarez PJJ Developmental toxicity in zebrafish (Danio rerio) embryos after exposure to manufactured nanomaterials: buckminsterfullerene aggregates (nC60) and fullerol. Environ Toxicol Chem. 2007;26(5):976–979. 10.1897/06-583.1 17521145
53 Nelson MA Domann FE Bowden GT Hooser SB Fernando Q Carter DE Effects of acute and subchronic exposure of topically applied fullerene extracts on the mouse skin. Toxicol Ind Health. 1993;9(4):623–630. 10.1177/074823379300900405 8296315
54 Roller M In vitro genotoxicity data of nanomaterials compared to carcinogenic potency of inorganic substances after inhalational exposure. Mutat Res. 2011;727(3):72–85. 10.1016/j.mrrev.2011.03.002 21458593
55 Matsuda S Matsui S Shimizu Y Matsuda T Genotoxicity of colloidal fullerene C60. Environ Sci Technol. 2011;45(9):4133–4138. 10.1021/es1036942 21480588
56 Shinohara N Matsumoto K Endoh S Maru J Nakanishi J In vitro and in vivo genotoxicity tests on fullerene C60 particles. Toxicol Lett. 2009;191(2-3):289–296. 10.1016/j.toxlet.2009.09.012 19772904
57 Totsuka Y Higuchi T Imai T Nishikawa A Nohmi T Kato T Masuda S Kinae N Hiyoshi K Ogo S Genotoxicity of nano/microparticles in in vitro micronuclei, in vivo comet and mutations assay systems. Part Fibre Toxicol. 2009;6:23. 10.1186/1743-8977-6-23 19725983
58 Jacobsen NR Pojana G White P Møller P Cohn CA Korsholm KS Vogel U Marcomini A Loft S Wallin H Genotoxicity, cytotoxicity, and reactive oxygen species induced by single-walled carbon nanotubes and C (60) fullerenes in the FE1-MutaMouse™ lung epithelial cells. Environ Mol Mutagen. 2008;49(6):476–487. 10.1002/em.20406 18618583
59 Ema M Tanaka J Kobayashi NNM Endoh S Maru J Hosoi M Nagai M Nakajima M Hayashi M Nakanishi J Genotoxicity evaluation of fullerene C60 nanoparticles in a comet assay using lung cells of intratracheally instilled rats. Regul Toxicol Pharmacol. 2012;62(3):419–424. 10.1016/j.yrtph.2012.01.003 22306441
60 Jacobsen NR Møller P Jensen KA Vogel U Ladefoged O Loft S Wallin H Lung inflammation and genotoxicity following pulmonary exposure to nanoparticles in ApoE −/− mice. Part Fibre Toxicol. 2009;6:2. 10.1186/1743-8977-6-2 19138394
61 Folkmann JK Risom L Jacobsen NR Wallin H Loft S Møller P Oxidatively damaged DNA in rats exposed by oral gavage to C60 fullerenes and single-walled carbon nanotubes. Environ Health Perspect. 2009;117(5):703–708. 10.1289/ehp.11922 19479010
62 Aoshima H Yamana S Nakamura S Mashino T Biological safety of water-soluble fullerenes evaluated using tests for genotoxicity, phototoxicity, and pro-oxidant activity. J Toxicol Sci. 2010;35(3):401–409. 10.2131/jts.35.401 20519849
63 Sayers BC Germolec DR Walker NJ Shipkowski KA Stout MD Cesta MF Roycroft JH White KL Baker GL Dill JA Respiratory toxicity and immunotoxicity evaluations of microparticle and nanoparticle C60 fullerene aggregates in mice and rats following nose-only inhalation for 13 weeks. Nanotoxicology. 2016;10(10):1458–1468. 10.1080/17435390.2016.1235737 27618498
64 Sayers BC Walker NJ Roycroft JH Germolec DR Baker GL Clark ML Hayden BK DeFord H Dill JA Gupta A Lung deposition and clearance of microparticle and nanoparticle C60 fullerene aggregated in B6C3F1 mice and Wistar Han rats following nose-only inhalation for 13 weeks. Toxicology. 2016;339:87–96. 10.1016/j.tox.2015.11.003 26612504
65 Nakamoto K McKinney MA Application of the correlation method to vibrational spectra of C60 and other fullerenes: predicting the number of IR-and Raman-active bands. J Chem Educ. 2000;77:775–780.10.1021/ed077p775
66 Hill MA, Watson CR, Moss OR. NEWCAS–An interactive computer program for particle size analysis. Richland, WA: Pacific Northwest Laboratory; 1977. PNL-2405, UC-32.
67 Brecher G Schneiderman M Time saving device for the counting of reticulocytes. Am J Clin Pathol. 1950;20(11):2079–2084. 10.1093/ajcp/20.11_ts.1079 14783090
68 National Toxicology Program (NTP). Specifications for the conduct of studies to evaluate the reproductive and developmental toxicity of chemical, biological and physical agents in laboratory animals for the National Toxicology Program (NTP). Research Triangle Park, NC: U.S. Department of Health and Human Services, National Institutes of Health, National Toxicology Program; 2011. https://ntp.niehs.nih.gov/ntp/test_info/finalntp_reprospecsmay2011_508.pdf
69 Maronpot RR Boorman GA Interpretation of rodent hepatocellular proliferative alterations and hepatocellular tumors in chemical safety assessment. Toxicol Pathol. 1982;10(2):71–80. 10.1177/019262338201000210 28094716
70 Boorman GA Montgomery CA Jr Eustis SL Wolfe MJ McConnell EE Hardisty JF Quality assurance in pathology for rodent carcinogenicity studies. Handbook of Carcinogen Testing. Park Ridge (NJ): Noyes Publications; 1985. p. 345–357.
71 Gart JJ Chu KC Tarone RE Statistical issues in interpretation of chronic bioassay tests for carcinogenicity. J Natl Cancer Inst. 1979;62(4):957–974. 285297
72 Dunnett CW A multiple comparison procedure for comparing several treatments with a control. J Am Stat Assoc. 1955;50:1096–1121.10.1080/01621459.1955.10501294
73 Williams DA A test for differences between treatment means when several dose levels are compared with a zero dose control. Biometrics. 1971;27(1):103–117. 10.2307/2528930 5547548
74 Williams DA The comparison of several dose levels with a zero dose control. Biometrics. 1972;28(2):519–531. 10.2307/2556164 5037867
75 Shirley E A non-parametric equivalent of Williams’ test for contrasting increasing dose levels of a treatment. Biometrics. 1977;33(2):386–389. 10.2307/2529789 884197
76 Williams DA A note on Shirley’s nonparametric test for comparing several dose levels with a zero-dose control. Biometrics. 1986;42(1):183–186. 10.2307/2531254 3719054
77 Dunn OJ Multiple comparisons using rank sums. Technometrics. 1964;6:241–252.10.1080/00401706.1964.10490181
78 Jonckheere AR A distribution-free k-sample test against ordered alternatives. Biometrika. 1954;41:133–145.10.1093/biomet/41.1-2.133
79 Dixon WJ Massey FJ Jr Introduction to statistical analysis. New York: McGraw Hill Book Company, Inc.; 1957.10.2307/2332898
80 Girard DM Sager DB The use of Markov chains to detect subtle variation in reproductive cycling. Biometrics. 1987;43(1):225–234. 10.2307/2531963 3567307
81 Code of Federal Regulations (CFR). 21(Part 58).
82 Witt KL Livanos E Kissling GE Torous DK Caspary W Tice RR Recio L Comparison of flow cytometry and microscopy-based methods for measuring micronucleated reticulocyte frequencies in rodents treated with nongenotoxic and genotoxic chemicals. Mutat Res. 2008;649(1-2):101–113. 10.1016/j.mrgentox.2007.08.004 17869571
83 Kissling GE Dertinger SD Hayashi M MacGregor JT Sensitivity of the erythrocyte micronucleus assay: dependence on number of cells scored and inter-animal variability. Mutat Res. 2007;634(1-2):235–240. 10.1016/j.mrgentox.2007.07.010 17851117
84 National Toxicology Program (NTP). TOX-87: Pathology tables, survival and growth curves from NTP short-term studies. Research Triangle Park, NC; 2020. 10.22427/NTP-DATA-TOX-87
85 Yamawaki H Iwai N Cytotoxicity of water-soluble fullerene in vascular endothelial cells. Am J Physiol Cell Physiol. 2006;290(6):C1495–C1502. 10.1152/ajpcell.00481.2005 16407415
86 Shinohara N Nakazato T Tamura M Endoh S Fukui H Morimoto Y Myojo T Shimada M Yamamoto K Tao H Clearance kinetics of fullerene C60 nanoparticles from rat lungs after intratracheal C60 instillation and inhalation C60 exposure. Toxicol Sci. 2010;118(2):564–573. 10.1093/toxsci/kfq288 20864628
87 Oberdörster G Ferin J Finkelstein G Wade P Corson N Increased pulmonary toxicity of ultrafine particles? II. Lung lavage studies. J Aerosol Sci. 1990;21:384–387.10.1016/0021-8502(90)90065-6
88 Oberdörster G. Toxicology of ultrafine particles: In vivo studies. Philosoph Trans R Soc. 2000; A 358:2719-2740.
89 Maynard AD Warheit DB Philbert MA The new toxicology of sophisticated materials: nanotoxicology and beyond. Toxicol Sci. 2011;120 Suppl 1:S109–S129. 10.1093/toxsci/kfq372 21177774
90 Morrow PE Possible mechanisms to explain dust overloading of the lungs. Fundam Appl Toxicol. 1988;10(3):369–384. 10.1016/0272-0590(88)90284-9 3286345
91 Morrow PE Dust overloading of the lungs: update and appraisal. Toxicol Appl Pharmacol. 1992;113(1):1–12. 10.1016/0041-008X(92)90002-A 1553742
92 Olin SS ILSI Risk Science Institute The relevance of the rat lung response to particle overload for human risk assessment: A workshop consensus report. Inhal Toxicol. 2000;12(1-2):1–17. 10.1080/08958370050029725 10715616
93 Masse R Fritsch P Nolike D LaFuma J Chretien J Cytokinetic study of alveolar macrophage renewal in rats. Pulmonary Macrophages and Epithelial Cells. Washington (D.C.): Energy Research and Development Administration, Technical Information Center; 1977. p. 106–114.
94 Tran CL Buchanan D Cullen RT Searl A Jones AD Donaldson K Inhalation of poorly soluble particles. II. Influence of particle surface area on inflammation and clearance. Inhal Toxicol. 2000;12(12):1113–1126. 10.1080/08958370050166796 11114784
95 Oberdörster G Lung particle overload: implications for occupational exposures to particles. Regul Toxicol Pharmacol. 1995;21(1):123–135. 10.1006/rtph.1995.1017 7784625
96 Kreyling WG Semmler M Erbe F Mayer P Takenaka S Schulz H Oberdörster G Ziesenis A Translocation of ultrafine insoluble iridium particles from lung epithelium to extrapulmonary organs is size dependent but very low. J Toxicol Environ Health A. 2002;65(20):1513–1530. 10.1080/00984100290071649 12396866
97 Möller W Felten K Sommerer K Scheuch G Meyer G Meyer P Häussinger K Kreyling WG Deposition, retention, and translocation of ultrafine particles from the central airways and lung periphery. Am J Respir Crit Care Med. 2008;177(4):426–432. 10.1164/rccm.200602-301OC 17932382
98 Oberdörster G, Sharp Z, Atudorei V, Elder A, Gelein R, Lunts A, Kreyling W, Cox C. Extrapulmonary translocation of ultrafine carbon particles following whole-body inhalation exposure of rats. J Toxicol Environ Health. 2002; A 65:1531-1543. 10.1080/00984100290071658
99 Luster MI Portier C Pait DG White KL Jr Gennings C Munson AE Rosenthal GJ Risk assessment in immunotoxicology. I. Sensitivity and predictability of immune tests. Fundam Appl Toxicol. 1992;18(2):200–210. 10.1016/0272-0590(92)90047-L 1534777
100 Uguccioni M D’Apuzzo M Loetscher M Dewald B Baggiolini M Actions of the chemotactic cytokines MCP-1, MCP-2, MCP-3, RANTES, MIP-1 alpha and MIP-1 beta on human monocytes. Eur J Immunol. 1995;25(1):64–68. 10.1002/eji.1830250113 7531149
101 Loetscher P Seitz M Clark-Lewis I Baggliolini M Moser B Monocyte chemotactic protein MCP-1, MCP-2, and MCP-3 are major attractants for human CD4+ and CD+ T lymphocytes. FASEB J. 1994;8(13):1055–1060. 10.1096/fasebj.8.13.7926371 7926371
102 Loetscher P Seitz M Clark-Lewis I Baggliolini M Moser B Activation of NK cells by CC chemokines. Chemotaxis, CA2+ mobilization, and enzyme release. J Immunol. 1996;156(1):322–327. 8598480
103 Menten P Wuyts A Van Damme J Macrophage inflammatory protein-1. Cytokine Growth Factor Rev. 2002;13(6):455–481. 10.1016/S1359-6101(02)00045-X 12401480
104 Dörger M Münzing S Allmeling AM Messmer K Krombach F Phenotypic and functional differences between rat alveolar, pleural, and peritoneal macrophages. Exp Lung Res. 2001;27(1):65–76. 10.1080/019021401459770 11202064
105 Sibille Y Reynolds HY Macrophages and polymorphonuclear neutrophils in lung defense and injury. Am Rev Respir Dis. 1990;141(2):471–501. 10.1164/ajrccm/141.2.471 2405761
106 Hasegawa M Sato S Takehara K Augmented production of chemokines (monocyte chemotactic protein-1 (MCP-1), macrophage inflammatory protein-lalpha (MIP-1alpha) and MIP-1beta) in patients with systemic sclerosis: MCP-1 and MIP-1alpha may be involved in the development of pulmonary fibrosis. Clin Exp Immunol. 1999;117(1):159–165. 10.1046/j.1365-2249.1999.00929.x 10403930
107 Smith RE Strieter RM Zhang K Phan SH Standiford TJ Lukacs NW Kunkel SL A role for C-C chemokines in fibrotic lung disease. J Leukoc Biol. 1995;57(5):782–787. 10.1002/jlb.57.5.782 7539030
108 Baran CP Opalek JM McMaken S Newland CA O’Brien JM Jr Hunter MG Bringardner BD Monick MM Brigstock DR Stromberg PC Important roles for macrophage colony-stimulating factor, CC chemokine ligand 2, and mononuclear phagocytes in the pathogenesis of pulmonary fibrosis. Am J Respir Crit Care Med. 2007;176(1):78–89. 10.1164/rccm.200609-1279OC 17431224
109 Byrne JD Baugh JA The significance of nanoparticles in particle-induced pulmonary fibrosis. McGill J Med. 2008;11(1):43–50. 18523535
110 Cesta MF Ryman-Rasmussen JP Wallace DG Masinde T Hurlburt G Taylor AJ Bonner JC Bacterial lipopolysaccharide enhances PDGF signaling and pulmonary fibrosis in rats exposed to carbon nanotubes. Am J Respir Cell Mol Biol. 2010;43(2):142–151. 10.1165/rcmb.2009-0113OC 19738159
111 Muller J Huaux F Moreau N Mission P Heilier JF Delos M Aras M Fonseca A Nagy JB Lison D Respiratory toxicity of multi-wall carbon nanotubes. Toxicol Appl Pharmacol. 2005;207(3):221–231. 10.1016/j.taap.2005.01.008 16129115
112 Braakhuis HM Park MVDZ Gosens I De Jong WH Cassee FR Physicochemical characteristics of nanomaterials that affect pulmonary inflammation. Part Fibre Toxicol. 2014;11:18. 10.1186/1743-8977-11-18 24725891