# Discussion

Differential pathological effects have been previously observed between nanoscale and microscale titanium dioxide (TiO_2_) particles of the same chemical composition and the same mass dose in the lungs of rodents.^33,87^ When the dose is expressed as surface area instead of mass, however, nanoscale and microscale particles share the same dose-response curve.^28,88^ Those observations, along with subsequent research in nanotoxicology, have highlighted the importance of understanding how chemical composition and physical properties influence toxicokinetics and toxicity.^89^ The current studies were designed to allow for comparisons of tissue burden and clearance kinetics between nanoscale and microscale C_60_ fullerenes. The exposure concentrations in these studies were selected to allow for comparison between the two particle sizes using either mass or estimated surface area as the dose metric.

In the current studies, initial lung burdens generally increased in proportion to exposure concentrations for both nano- and micro-C_60_ particles. In addition, rapid clearance of C_60_ from the lung was observed during the first 14 days of the postexposure period for both particle sizes at all exposure concentrations except for 30 mg/m^3^ micro-C_60_ groups in both species. Relatively large lung burdens and increased retention half-lives are characteristic of lung overload. Morrow’s overload hypothesis^90,91^ is applicable to poorly soluble particles of low toxicity (e.g., carbon black, coal dust, diesel soot, talc, and titanium dioxide). Experiments in F344 rats demonstrated a slowing of pulmonary clearance when the volume of particles in the lung reaches 6% of the volume of alveolar macrophages and a ceasing of clearance when the particle volume reaches 60%.^90,91^ In rats, but not mice or hamsters, inhalation exposure to certain particles at concentrations that result in lung overload has been associated with a variety of nonneoplastic lung lesions including inflammation, fibrosis, epithelial hyperplasia, and lung tumors.^92^ Lung burdens, similar to those that result in lung overload in rats, have been observed in humans. Induction of lung fibrosis has been observed in both rats and humans, whereas lung tumors were observed only in rats.

The possibility that lung overload resulted from exposure to nano- or micro-C_60_ was evaluated in the present studies.^93^ Using a density of 1.72 g/cm^3^ and the lung burdens determined immediately after exposure, Sayers et al. calculated the volume of particles in the lungs and compared it to the volume corresponding to 6% of the volume of alveolar macrophages (1.8 × 10^9^ for rats and 2.4 × 10^8^ for mice) using a lung alveolar macrophage cell number derived for Sprague Dawley rats and scaled to mice using relative lung weights.^93^ The volume of particles exceeded the overload volume in male rats and mice exposed to 30 mg/m^3^ of micro-C_60_. Tran et al.^94^ demonstrated that surface area of the retained lung burden is also an appropriate metric for determining if lung overload has occurred. Using the average estimated surface-area-to-mass ratios and the lung burdens determined immediately after exposure, the estimated surface area of particles in the lungs was calculated by Sayers et al. and compared to the particle surface area thought to result in overload (300 cm^2^ for rats scaled to 32 cm^2^ for mice using relative lung weights).^94^ The estimated surface area of particles exceeded this surface area at 30 mg/m^3^ for micro-C_60_ and at 2 mg/m^3^ for nano-C_60_, in both rats and mice. Overall, the estimated surface-area-based lung overload calculations were in good agreement with the pulmonary clearance data. Although both volumetric and surface-area-based lung overload were apparent at the higher exposure concentrations following exposure to both particle sizes in the present studies, a notable finding is that the retention half-lives observed with both nano- and micro-C_60_, in particular following exposure to lower concentrations of either particle size, were shorter than those typically observed with poorly soluble particles (~70 days in rats).^95^ The retention half-life data in the current study are similar to those observed in a previous study, where retention half-lives of 26 and 29 days were observed in rats following exposure to nano- or micro-C_60_, respectively.^11^

At an equivalent exposure concentration (2 mg/m^3^), the lung burden of C_60_ on postexposure day 0 was consistently greater in both species following inhalation of nano-C_60_ particles compared to micro-C_60_. In rats, nano-C_60_ exposure resulted in lung burdens 32% (males) and 87% (females) greater than C_60_ lung burdens following micro-C_60_ exposure. Similar findings were observed in a 10-day nose-only inhalation study comparing nano-C_60_ (count median diameter [CMD]: 55 nm) and micro-C_60_ particles (mass median aerodynamic diameter [MMAD]: 0.93 µm); the lung burden immediately after exposure to nano-C_60_ particles was 41% greater than micro-C_60_ particle exposure in male rats.^11^ In the present studies, the difference in lung burden between the two particle sizes (nano-C_60_ versus micro-C_60_) was greater in mice than in rats; in mice, the lung burden immediately after exposure was approximately threefold greater following nano-C_60_ exposure compared to following micro-C_60_ exposure in both sexes. Of note, however, is that although steady-state lung burden was likely achieved in rats exposed to micro-C_60_ particles at 2 mg/m^3^, this was not the case in rats exposed to nano-C_60_ particles at the same exposure concentration. As such, the difference in lung concentrations and burdens between the two different particle sizes likely would have been greater in rats following longer exposure duration.

The differences in C_60_ lung deposition between the two particle sizes at the same exposure concentration (2 mg/m^3^) were greater in mice than in rats, but the opposite pattern was observed in terms of clearance parameters between the species. In mice, the clearance rate constants (0.047, nano-C_60_; 0.044 days^−1^, micro-C_60_; respectively) and half-lives (15 days, nano-C_60_; 16 days, micro-C_60_; respectively) were very similar. In rats, the C_60_ clearance rate was about twofold greater (0.026 days) following micro-C_60_ exposure than following nano-C_60_ exposure (0.011 days^−1^). Likewise, the half-life of C_60_ following nano-C_60_ exposure (61 days) was about twofold longer than the half-life of C_60_ following micro-C_60_ exposure (27 days). In a previous study, following a 10-day inhalation exposure in male rats, the half-lives of C_60_ particles were very similar, 26 days compared to 29 days for nano-C_60_ or micro-C_60_ particles, respectively, at the same exposure concentration (2 mg/m^3^) for both particle sizes.^11^ These observations, along with the current studies, highlight the effect of interspecies differences and exposure duration on particle elimination kinetics between the nanometer and micrometer particles. Interestingly, in rats, the half-life of C_60_ particles following nano-C_60_ exposure at 2 mg/cm^3^ was similar to the half-life of C_60_ particles following micro-C_60_ exposure at higher exposure concentrations (15 and 30 mg/cm^3^).

Shinohara et al.,^86^ proposed a two-compartment model to describe the clearance of inhaled C_60_ particles from the lung, with compartment one representing the alveolar surface and compartment two representing the lung interstitium or alveolar epithelial cells. According to this model, phagocytosis by alveolar macrophages is responsible for rapid clearance of C_60_ from compartment one. C_60_ particles that penetrate the epithelial barrier are slowly cleared by translocation to the lymph nodes. Important to note is that some fraction of the measured retained dose was likely also localized to compartments other than macrophages, like the interstitium or within epithelial cells. This suggests that 90% of instilled C_60_ particles in the current study were eliminated by rapid clearance from compartment one. Shinohara et al.^86^ also used the two-compartment model to calculate the half-life of C_60_ from data originally reported using a one-compartment model by Baker et al.^11^ The half-life calculated by both models is similar, suggesting that the one-compartment and two-compartment models estimate similar clearance dynamics of C_60_ from the lung.

Previous reports suggest the translocation of inhaled particles to extrapulmonary tissues is minimal (<1%).^96,97^ In the current study, C_60_ fullerenes were detected in bronchial lymph nodes, liver tissue, and spleen tissue following both nano- and micro-C_60_ particle exposure, but most of the samples were below the estimated limit of quantitation (ELOQ). The ELOQ concentrations (0.06 to 0.61 mg C_60_/g tissue) indicate that the C_60_ burdens in liver and spleen tissues were less than 1% of the C_60_ burdens measured in lung tissue (≥130 mg C_60_/g tissue). C_60_ was not detected in blood, brain, or kidney tissues following exposure to either particle size. In a similar study comparing the toxicity and tissue burden between nano- and micro-C_60_ particle inhalation exposure for 10 days, C_60_ fullerenes were not detected in blood samples for either particle size.^11^ In another whole-body inhalation study, ^13^C elemental carbon nanoparticles (22 to 30 nm) were used to evaluate extrapulmonary translocation.^98^ In this study, ^13^C was detected in liver tissue but not heart, brain, or kidney tissues. As noted by these authors, the extrapulmonary translocation of ^13^C could be the result of a combination of direct particle deposition into the lungs and translocation into the blood, and also translocation up into the gastrointestinal tract by the mucociliary escalator. In the present studies, C_60_ was not detected in the blood, which suggests that either extrapulmonary translocation did not occur to the blood, C_60_ concentrations in the blood were below the limit of detection, or C_60_ was rapidly cleared from the blood.

The only extrapulmonary site of potential toxicity was the testis. A low incidence of germinal epithelium degeneration was observed in the testes of male rats in each micro-C_60_ exposure group. Germinal epithelium degeneration also was observed in testes of three male rats exposed to 2 mg/m^3^ nano-C_60_. Germinal epithelium degeneration was not seen in air controls in the study. This lesion is generally a relatively common background lesion in rats, so these occurrences alone do not indicate a treatment-related effect. Because sperm motility was slightly lower in male rats and mice in all micro-C_60_ exposed groups, however, an effect of micro-C_60_ on the rat testis cannot be ruled out.

The toxicity of C_60_ fullerene nanoparticles and microparticles following nose-only inhalation was evaluated in the current studies. The results demonstrated that inhalation of C_60_ at concentrations up to 2 mg/m^3^ (nano-C_60_) and 30 mg/m^3^ (micro-C_60_) did not affect systemic immune function in mice or rats, as indicated by a lack of effects on the antibody-forming cell (AFC) assay and minimal effects on the numbers of specific cell types in the spleen. The AFC assay, as described in Luster et al.,^99^ is considered the most sensitive and predictive test of immune function, and, when combined with other immune assays (i.e., plaque-forming cell responses and surface marker analysis), is an accurate predictor (91%) of systemic immunotoxicity. In addition, NTP has historically used only female rodents for immunotoxicology studies, as females tend to be more immunologically responsive than their male counterparts, which allows for the detection of subtle immunological effects. Decreased spleen cell numbers were observed (on a mass basis) in mice exposed to 2 mg/m^3^ nano-C_60_; however, the total spleen cell number of the control group of mice assigned (randomly) to the nano-C_60_ study was higher than in any other group, including the control animals in the micro-C_60_ test group, and thus the difference in total spleen cell numbers does not appear to be biologically relevant. Although minimal effects on observational parameters (spleen cell numbers and phenotypes in mice) were noted, those effects were not supported by functional changes. Given the observed effects on the immune system were minimal, additional immunologic effects are unlikely to have been observed if male animals had been included in the immunotoxicity study.

In the current studies, inflammatory effects (histiocytic infiltration, pigmentation, and chronic inflammation) were noted in lung histopathology. These findings are consistent with previous reports of inflammation induced by C_60_ particles.^6,39,59^ By comparison, the inflammatory response in the 15 mg/m^3^ and 30 mg/m^3^ micro-C_60_ was more pronounced than that of the 2 mg/m^3^ nano-C_60_, consistent with the more highly deposited mass of C_60_ in the lung with the micro-C_60_ at 15 and 30 mg/m^3^ compared to that observed in the nano-C_60_ study at 2 mg/m^3^. Comparisons of the incidence and average severity results from evaluations of lung histopathology in both rats and mice indicated that the nano-C_60_ test article initiated a greater inflammatory response compared to micro-C_60_ test article at the same mass-based exposure concentration (2 mg/m^3^). The higher measured surface area/mass of the nano-C_60_ particle suggests the inflammatory response is driven by a surface area dose. As noted by Sayers et al.^63^ using the data from this study, the surface areas of the exposure atmospheres for the 2 mg/m^3^ nano-C_60_ (0.112 m^2^/m^3)^ was within the range of the calculated surface areas of the 15 mg/m^3^ (0.084 m^2^/m^3^) and 30 mg/m^3^ (0.167 m^2^/m^3^) micro-C_60_ exposure atmospheres. Estimates of the surface area of the deposited C_60_, made by Sayers et al.^64^ using the lung burden data and surface areas of the respective C_60_ particles, indicated that at the 2 mg/m^3^ the estimated surface area of deposited C_60_ in the lung was higher for nano-C_60_ exposed animals as compared to animals exposed to micro-C_60_ at the 15 mg/m^3^ and 30 mg/m^3^. This implies that the inflammatory response is not driven by the surface area. That the estimates made by Sayers et al. of the surface area of the deposited C_60_ in the lung assumes lack of aggregation in vivo, however, should be noted and thus might be inaccurate and likely overestimate the deposited surface area of the nano-C_60_.

Significant, concentration-related increases in MCP-1 (rats) and MIP-1α (mice) following C_60_ inhalation were observed in the present studies. These data are consistent with a study demonstrating that C_60_ inhalation (0.2 mg/m^3^) for 4 weeks increased the expression of genes associated with MCP-1 and MIP-1α.^28^ Interestingly, differential effects were observed in BALF levels of both MIP-1α and MCP-1 between animals exposed to nano-C_60_ and micro-C_60_ that could not be accounted for by using surface area as the basis of exposure. MCP-1, also known as chemokine (C-C motif) ligand 2 (CCL2), is a potent chemoattractant for monocytes.^100^ However, MCP-1 has also been shown to have chemoattractant effects on other immune cells, including T cells^101^ and NK cells.^102^ MIP-1α, another chemokine, can be secreted by a wide variety of immune cell types, including monocytes and macrophages, T and B lymphocytes, NK cells, dendritic cells, neutrophils, and eosinophils.^103^ Increased production of MIP-1α is associated with inflammation due to its chemotactic effects on several cell types, including monocytes, T cells, neutrophils, eosinophils, basophils, dendritic cells, and NK cells.

The use of CD11b and CD163 in these studies for delineating cell types in the BALF did not allow distinct cell types to be determined, as both the double-positive and double-negative cell populations could contain numerous cell types. Most likely is that the double-negative (i.e., CD163^−^CD11b^−^) population of rat BALF cells in the present studies consisted primarily of alveolar macrophages (AM), in addition to a smaller population of other cell types, including T and B lymphocytes, NK cells, eosinophils, and mast cells, which can all be recovered from BALF in low numbers.^104^ Cells staining positive for both CD163 and CD11b were most likely a combination of resident airway macrophages, which have been identified throughout the respiratory tract,^105^ and macrophages recruited to the lung. Cells staining positive for CD11b only (i.e., CD163^−^CD11b^+^) were neutrophils and other myeloid cells. Significant increases in the percentage and absolute numbers of CD163^−^CD11b^+^ neutrophils were observed in rats exposed to 30 mg/m^3^ micro-C_60_, which correlated with a significant increase in neutrophils in rats in the same exposure group identified by BALF differential cell counting. Unfortunately, cellular origin is not determined for macrophages identified by differential cell counting.

These studies demonstrated that the immune effects of C_60_ fullerene inhalation in rats and mice were limited primarily to the lung, where dramatically increased levels of the monocyte/macrophage chemotactic and inflammatory cytokines MCP-1 and MIP-1α were detected in BALF. Increases in MCP-1 and MIP-1α have been linked to the formation of pulmonary fibrosis in rodents and humans.^103,106,107^ In fact, the absence of MCP-1 in CCL2^−/−^ mice conferred protection against bleomycin-induced pulmonary fibrosis.^108^ In humans, pneumoconiosis, or particle-induced pulmonary fibrosis, has been documented in several cases of occupational exposure to particulates, although no human cases of pulmonary fibrosis directly linked to nanomaterial exposure have been documented.^109^ Nanomaterial-mediated pulmonary fibrosis, however, has been observed in Sprague Dawley rats as soon as 21 days and persisting for at least 60 days following a single intratracheal instillation of multiwalled carbon nanotubes.^110,111^ Further, that nanoparticles are the fraction of inhaled particulates that contribute most significantly to pulmonary fibrosis in humans has been suggested.^109^

In conclusion, the lung deposition of nano-C_60_ particles was greater than lung deposition of micro-C_60_ particles in both rats and mice following exposure to the same mass-based exposure concentration for both particle sizes (2 mg/m^3^). Although the clearance kinetics were similar between nano- and micro-C_60_ particles in male mice, in male rats, the elimination rate of nano-C_60_ particles was about half that of micro-C_60_ particles. On an estimated surface-area basis, exposure to 2 mg/m^3^ nano-C_60_ resulted in a similar lung burden as exposure to 30 mg/m^3^ of micro-C_60_. This was also the case for 0.5 mg/m^3^ nano-C_60_ and 15 mg/m^3^ micro-C_60_. The data from these studies provide comparative information regarding how particle size influences the deposition and clearance of C_60_ fullerenes.

The mild pulmonary inflammation observed in rats and mice exposed to fullerenes is consistent with the response observed following inhalation of other nanoparticles. Pulmonary inflammation is the most commonly reported effect of inhaled nanoparticles.^112^ Lung inflammatory responses were observed, primarily at the higher exposure concentrations. Inflammatory effects of nano-C_60_ exposure were, in general, more severe than micro-C_60_ exposure when comparing both particle sizes at the same mass-based exposure concentration.