# Results

## Data Availability

The National Toxicology Program (NTP) evaluated all study data. Data relevant for evaluating toxicological findings are presented here. All study data are available in the NTP Chemical Effects in Biological Systems (CEBS) database: https://doi.org/10.22427/NTP-DATA-TOX-87.^84^

## Three-month Studies in Rats

### Lung Burden

Tissue burden data for rats are presented in Appendix B. In the current studies, lung weights (g) and lung C_60_ concentrations (μg C_60_/g lung) were determined in male and female rats following the last exposure. In addition, lung burdens were assessed in male rats only 14, 28, and 56 days after exposure to assess lung clearance rates. Total C_60_ lung burden (μg C_60_/lung) and exposure-concentration-normalized lung burden (μg C_60_/lung per mg C_60_/m^3^) were calculated. Due to the increased lung weights in exposed rats, lung burdens, instead of lung tissue concentrations, were used to calculate lung clearance rates.

In the micro-C_60_ study, lung weights were significantly increased 14 and 56 days postexposure in males exposed to 30 mg/m^3^ relative to control animals (Table B-1). Lung weights were significantly increased in males 56 days postexposure to 15 mg/m^3^, relative to control animals. There were no significant differences in lung weights of females. In the nano-C_60_ study, males exposed to 0.5 mg/m^3^ had significantly increased lung weights 28 days postexposure (Table B-3). There were no significant differences in lung weights of females.

Lung burden rapidly decreased 14 days postexposure in male rats exposed to all concentrations of micro-C_60_, with the exception of the groups exposed to 30 mg/m^3^ (Table B-1). Clearance decreased between postexposure days 14 and 28 in males exposed to all concentrations, with the exception of the group exposed to 30 mg/m^3^. Lung burden rapidly decreased between postexposure days 14 and 28 in males exposed to 30 mg/m^3^. Clearance decreased rapidly between postexposure days 28 and 56 in males in all exposure concentration groups. In the nano-C_60_ study, lung burden rapidly decreased 14 days postexposure in males exposed to all concentrations (Table B-3). Clearance decreased between postexposure days 14 and 28 in males exposed to all concentrations. Clearance decreased rapidly between postexposure days 28 and 56 in males at all concentrations.

In the micro-C_60_ study, normalized retained lung burdens were higher with increasing exposure concentration at postexposure days 28 and 56 in males (Table B-1). There were no exposure concentration-related effects on normalized lung burden in females.

In the nano-C_60_ study, normalized lung burdens (μg C_60_/lung per mg C_60_/m^3^) at postexposure day 0 were higher in both males and females exposed to 0.5 mg/m^3^ relative to groups exposed to 2 mg/m^3^. In the clearance study (males only), burdens were marginally higher at postexposure days 14 and 28 (Table B-3).

Lung deposition and clearance parameters for male rats were calculated from C_60_ burden data (Table 2). In the micro-C_60_ study, the clearance rate constant (k) was determined to be approximately twofold greater in male rats exposed to 2 mg/m^3^ than in rats exposed to 15 and 30 mg/m^3^, which had comparable k values. In the nano-C_60_ study, the clearance rate constant was determined to be greater in male rats exposed to 0.5 mg/m^3^ than in those exposed to 2 mg/m^3^, and the clearance rate constant of the 2 mg/m^3^ exposure group was comparable to those of the 15 and 30 mg/m^3^ groups in the micro-C_60_ study. At the same mass-based exposure concentration, 2 mg/m^3^, clearance rate constant of the 1 µm particles was more than twofold greater than the clearance rate constant of the 50 nm particles.

Table 2 Lung Deposition and Clearance Parameter Estimates for Male Rats Exposed to Fullerene C_60_^a^

Parameter | 0.5 mg/m^3^ | 2 mg/m^3^ | 15 mg/m^3^ | 30 mg/m^3^
Micro-C_60_ (1 µm)
A_0_ (µg fullerene C_60_/total lung) | | 416 | 2,037 | 6,032
k (days^−1^) | | 0.026 | 0.010 | 0.013
t_1/2_ (days) | | 27 | 69 | 55
α (µg fullerene C_60_/total lung per day) | | 12 | 35 | 113
A_e_ (µg fullerene C_60_/total lung) | | 465 | 3,472 | 9,010
Nano-C_60_ (50 nm)
A_0_ (µg fullerene C_60_/total lung) | 185 | 604
k (days^−1^) | 0.018 | 0.011
t_1/2_ (days) | 38 | 61
α (µg fullerene C_60_/total lung per day) | 4.2 | 10.8
A_e_ (µg fullerene C_60_/total lung) | 229 | 946

A_0_ = lung burden at t = 0 days postexposure; k = first-order lung clearance rate constant; t_1/2_ = lung clearance half-life; α = lung deposition rate; A_e_ = steady-state lung burden.

^a^ Data presented as mean values.

In male rats exposed to micro-C_60_, clearance half-life (t_1/2_) increased between exposure concentrations of 2 and 15 mg/m^3^ (27 and 69 days, respectively), and then decreased to 55 days in rats exposed to 30 mg/m^3^ (Table 2). In male rats exposed to nano-C_60_, the calculated clearance half-life increased between exposure concentrations of 0.5 mg/m^3^ and 2 mg/m^3^ (38 and 61 days, respectively). In the nano-C_60_ study, the t_1/2_ of 2 mg/m^3^ was longer than that in animals exposed to the same concentration in the micro-C_60_ study (61 versus 27 days, respectively).

Assuming clearance is a first-order process over time, steady-state lung burdens would be reached in approximately five half-lives. In the micro-C_60_ study, immediately following exposure to 2 mg/m^3^, lung burden in males was measured at 439 µg C_60_/total lung (Table B-1) and represented 94% of the calculated steady-state lung burden (465 µg C_60_/lung) (Table 2). Steady-state lung burdens were likely not reached in males exposed to 15 or 30 mg/m^3^ micro-C_60_. In the nano-C_60_ study, immediately following exposure to 2 mg/m^3^, lung burden in males was 581 µg C_60_/total lung (Table B-3) and represented 61% of the calculated steady-state lung burden (946 µg C_60_/lung) (Table 2). Steady-state lung burdens were likely not reached in males exposed to 2 mg/m^3^ nano-C_60_.

### General Toxicity

In the micro-C_60_ study, all males survived to the end of the study (Table 3). One 2 mg/m^3^ female was euthanized moribund on day 88 of the study, which was not considered related to exposure. Final mean body weights and mean body-weight gains of exposed groups of males and females were similar to those of the control groups (Table 3 and Figure 4). There were no clinical findings in males or females considered to be exposure related. In the nano-C_60_ study, all males and females survived to the end of the study (Table 4 and Figure 5). Final mean body weights and mean body weight gains of exposed groups of males and females were similar to those of the control groups (Table 4 and Figure 4). No clinical findings in males or females were deemed related to exposure.

Table 3 Survival and Body Weights of Rats in the Three-month Nose-only Inhalation Study of Fullerene Micro-C_60_ (1 µm)^a^

Concentration (mg/m^3^) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 10/10 | 143 ± 4 | 353 ± 12 | 210 ± 10
2 | 10/10 | 139 ± 2 | 350 ± 10 | 210 ± 11 | 99
15 | 10/10 | 144 ± 4 | 373 ± 16 | 229 ± 14 | 106
30 | 10/10 | 143 ± 4 | 368 ± 9 | 224 ± 8 | 104
Female
0 | 10/10 | 124 ± 3 | 222 ± 8 | 98 ± 6
2 | 9/10^c^ | 127 ± 3 | 222 ± 7 | 96 ± 5 | 100
15 | 10/10 | 123 ± 3 | 211 ± 6 | 88 ± 4 | 95
30 | 10/10 | 121 ± 2 | 224 ± 7 | 103 ± 6 | 101

^a^ Weights and weight changes are presented as mean ± standard error. Subsequent calculations are based on animals surviving to the end of the study. Differences from the control group are not significant by Dunnett’s test.

^b^ Number of animals surviving at 13 weeks/number initially in group.

^c^ Week of death: 13.

Figure 4

Growth Curves for Rats Exposed to Fullerene Micro-C_60_ (1 µm) by Nose-only Inhalation for Three Months

Table 4 Survival and Body Weights of Rats in the Three-month Nose-only Inhalation Study of Fullerene Nano-C_60_ (50 nm)^a^

Concentration (mg/m^3^) | Survival^b^ | Initial Body Weight(g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 10/10 | 152 ± 3 | 362 ± 10 | 210 ± 9
0.5 | 10/10 | 146 ± 3 | 360 ± 12 | 215 ± 9 | 100
2 | 10/10 | 150 ± 4 | 356 ± 9 | 207 ± 8 | 99
Female
0 | 10/10 | 118 ± 3 | 207 ± 6 | 89 ± 4
0.5 | 10/10 | 117 ± 2 | 207 ± 7 | 89 ± 6 | 100
2 | 10/10 | 115 ± 2 | 201 ± 3 | 86 ± 3 | 97

^a^ Weights and weight changes are presented as mean ± standard error. Differences from the control group are not significant by Dunnett’s test.

^b^ Number of animals surviving at 13 weeks/number initially in group.

Figure 5

Growth Curves for Rats Exposed to Fullerene Nano-C_60_ (50 nm) by Nose-only Inhalation for Three Months

Following exposure to micro-C_60_, absolute and relative liver weights of 30 mg/m^3^ males were significantly greater than those of the control animals (Appendix H). There were no exposure-related changes in organ weights in females. There were no exposure-related changes in organ weights in males or females exposed to nano-C_60_ (Appendix H).

### Clinical Pathology

The summary clinical pathology data for rats exposed to micro-C_60_ can be found in Appendix H. No changes in the hematological parameters were attributable to inhalation exposure. A few statistically significant results were found in the serum chemistry data, including minimal increase in glucose in the 15 mg/m^3^ males and minimal decrease in alanine aminotransferase in the 30 mg/m^3^ males; none of these changes were considered toxicologically significant.

The summary clinical pathology data for rats exposed to nano-C_60_ can be found in Appendix H. No treatment-related changes in the hematological parameters occurred in male or female rats. A few statistically significant results were found in the serum chemistry data, including minimal decreases in albumin and in the albumin-to-globulin ratio (A:G) in the 2 mg/m^3^ males and decreased bile acids in the 2 mg/m^3^ females; none of these changes were considered toxicologically significant.

### Reproductive Evaluations

Male rats exposed to micro-C_60_ displayed no changes in reproductive organ weights or sperm counts. Sperm motility was slightly lower in all exposed groups (74% to 80% in exposed groups compared to 84% in controls) (Table A-1). Histopathological findings were observed at low incidences in the testes (germinal epithelium, degeneration) in all exposed groups (Table 5). Males exposed to nano-C_60_ displayed no changes in reproductive organ weights or sperm counts. Sperm motility was slightly lower in rats exposed to 2 mg/m^3^ nano-C_60_ (71% compared to 85% in controls) (Table A-2). Histopathological findings in the testes (germinal epithelium, degeneration) and epididymis (hypospermia) also were observed at this exposure level (Table 6).

Table 5 Incidences of Selected Nonneoplastic Lesions in Rats in the Three-month Nose-only Inhalation Study of Fullerene Micro-C_60_ (1 µm)

| 0 mg/m^3^ | 2 mg/m^3^ | 15 mg/m^3^ | 30 mg/m^3^
Male
Lymph Node, Bronchial^a^ | 7 | 5 | 6 | 8
Pigmentation^b^ | 0 | 1 (1.0)^c^ | 3 (1.0) | 7** (1.9)
Lymph Node, Mediastinal | 8 | 9 | 8 | 9
Pigmentation | 4 (1.0) | 4 (1.0) | 3 (1.7) | 5 (1.6)
Lung | 10 | 10 | 9 | 10
Infiltration cellular, histiocyte | 1 (1.0) | 1 (1.0) | 8** (1.4) | 10** (3.8)
Inflammation, chronic active | 1 (1.0) | 4 (1.0) | 8** (1.8) | 10** (2.0)
Pigmentation | 0 | 1 (1.0) | 8** (2.1) | 10** (3.2)
Testes | 10 | 10 | 10 | 10
Germinal epithelium, degeneration | 0 | 1 (1.0) | 3 (2.0) | 1 (1.0)
Female
Lymph Node, Bronchial | 6 | 5 | 7 | 5
Pigmentation | 1 (1.0) | 1 (1.0) | 3 (1.3) | 4 (1.5)
Lymph Node, Mediastinal | 8 | 10 | 8 | 9
Pigmentation | 3 (1.0) | 9* (1.1) | 7 (1.3) | 7 (1.6)
Lung | 10 | 10 | 10 | 10
Infiltration cellular, histiocyte | 1 (1.0) | 1 (1.0) | 8** (1.0) | 10** (4.0)
Inflammation, chronic active | 0 | 0 | 1 (1.0) | 10** (2.0)
Pigmentation | 0 | 0 | 8** (2.3) | 10** (3.2)

* Significantly different (p ≤ 0.05) from the control group by the Fisher exact test; **p ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Table 6 Incidences of Selected Nonneoplastic Lesions in Rats in the Three-month Nose-only Inhalation Study of Fullerene Nano-C_60_ (50 nm)

| 0 mg/m^3^ | 0.5 mg/m^3^ | 2 mg/m^3^
Male
Lymph Node, Bronchial^a^ | 10 | 9 | 10
Pigmentation^b^ | 0 | 3 (1.0)^c^ | 4* (1.0)
Lymph Node, Mediastinal | 10 | 8 | 10
Pigmentation | 1 (1.0) | 6* (1.0) | 2 (1.0)
Lung | 10 | 10 | 10
Infiltration cellular, histiocyte | 1 (1.0) | 1 (1.0) | 3 (1.3)
Pigmentation | 0 | 0 | 3 (1.0)
Kidney | 10 | 10 | 10
Nephropathy | 1 (1.0) | 1 (1.0) | 6* (1.0)
Epididymis | 10 | 10 | 10
Hypospermia | 0 | 0 | 2 (3.0)
Testes | 10 | 10 | 10
Germinal epithelium, degeneration | 0 | 0 | 3 (2.0)
Female
Lymph Node, Bronchial | 10 | 10 | 10
Pigmentation | 0 | 1 (1.0) | 5* (1.2)
Lymph Node, Mediastinal | 8 | 8 | 10
Pigmentation | 0 | 7** (1.0) | 9** (1.3)
Lung | 10 | 10 | 10
Infiltration cellular, histiocyte | 2 (1.0) | 1 (1.0) | 8* (1.0)
Pigmentation | 0 | 0 | 8** (2.0)

Significantly different (p ≤ 0.05) from the control group by the Fisher exact test; **p ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

### Histopathology

#### Micro-C_60_ Study

Exposure-related gross lesions were limited to brown discoloration (presumably the test article) of the lungs of all male and female rats in the 15 and 30 mg/m^3^ groups and many rats in the 2 mg/m^3^ groups. Histologically, exposure-related lesions were present in the lung and bronchial and mediastinal lymph nodes. A complete summary of histopathological findings can be found in Appendix H.

Lung: Exposure-related findings in the lung of rats were limited to infiltration cellular, histiocyte (increased numbers of alveolar macrophages in the alveoli), chronic active inflammation, and pigmentation (presumed to be the test article) (Table 5). The incidence of infiltration cellular, histiocyte was statistically significant compared to controls in the 15 and 30 mg/m^3^ groups in both sexes. In males, the average severity was increased in the 15 and 30 mg/m^3^ groups (1.4 and 3.8, respectively) compared to the controls (in which the average severity was minimal, 1.0). In females, the average severity was minimal (1.0) in the controls and in the 2, and 15 mg/m^3^ groups, but was marked in all animals in the 30 mg/m^3^ group. The incidence of chronic inflammation in the males was increased in all exposed groups compared to the control group, but the increase was statistically significant only in the 15 and 30 mg/m^3^ groups. In the females, the incidences of chronic inflammation were increased in the 15 and 30 mg/m^3^ groups, and the increase was statistically significant in the 30 mg/m^3^ group. The severity generally increased with increasing exposure concentration. In males, pigment was seen in all exposed groups and the severity increased with increasing exposure concentration. In females, pigment was seen in the 15 and 30 mg/m^3^ groups only, and the severity increased with increasing exposure.

Infiltration cellular, histiocyte was characterized by the accumulation of alveolar macrophages within the lungs. The alveolar macrophages were enlarged, had foamy cytoplasm, and often contained pigment (Figure 8 and Figure 9). The pigment was golden brown to dark brown and mostly small granules; larger granules were darker brown and refractile. The pigment was presumed to be the test article because it was not seen in the control animals. Chronic active inflammation was characterized by thickened alveolar septa, a mixed population of inflammatory cells, primarily macrophages and lymphocytes with fewer plasma cells and occasional neutrophils, and increased numbers of type II pneumocytes (Figure 10). These foci of inflammation were typically associated with areas of histiocyte infiltration. One control rat was diagnosed with chronic active inflammation; however, the distribution of inflammation in this animal differed from that of the exposed animals in that it was found at the periphery of the lung. Inflammation in the control animal was considered to be the background form of chronic active inflammation often seen in rodents, whereas inflammation in the exposed animals was associated with the pigment-containing macrophages and was considered exposure-related.

Figure 8

Infiltration Cellular, Histiocyte and Pigmentation in the Lung of a Male Wistar Han Rat Exposed to 30 mg/m3 Micro-C60 by Nose-only Inhalation for Three Months (H&E, 20×)

The golden-brown pigment within the alveolar macrophages is presumed to be the test article.

Figure 9

Infiltration Cellular, Histiocyte and Pigmentation in the Lung of a Male Wistar Han Rat Exposed to 2 mg/m3 Nano-C60 by Nose-only Inhalation for Three Months (H&E, 40×)

Figure 10

Chronic Active Inflammation in the Lung of a Male Wistar Han Rat Exposed to 30 mg/m3 micro-C60 by Nose-only Inhalation for Three Months (H&E, 40×)

In addition to the macrophages, lymphocytes, neutrophils, and increased numbers of alveolar type II cells are present.

Bronchial and mediastinal lymph nodes: In both sexes, pigment was observed in the bronchial and mediastinal lymph nodes (Table 5). A few control rats had pigment in the lymph nodes, but there was a statistically significant increase in incidence in the bronchial lymph node of 30 mg/m^3^ males and the mediastinal lymph node of 2 mg/m^3^ females. In most cases, however, the average severity was higher in the exposed groups than in controls. The pigment was present within macrophages in the subcapsular sinus or cortex. In some cases, pigment was present in control animals or was present in areas of hemorrhage. The pigment was morphologically indistinguishable from that seen in the lung (presumed test article). The lesions were morphologically identical to the lymph node lesions seen in rats exposed to nano-C_60_ particles.

Other lesions: In the testes, one animal in the 2 mg/m^3^ group, three in the 15 mg/m^3^ group, and one in the 30 mg/m^3^ group had degeneration of the germinal epithelium compared to none in the control group (Table 5). The incidences were not statistically significant, and as this is a common background lesion in rats, the significance of this finding is unclear.

#### Nano-C_60_ Study

Exposure-related gross lesions were limited to slight brown discoloration of the lungs of several rats in both exposure groups (whereas in the micro-C_60_ studies, the lungs of many rats in the 2 mg/m^3^ and all rats in the 15 and 30 mg/m^3^ groups were brown at necropsy). Histologically, exposure-related lesions were found in the lung and bronchial and mediastinal lymph nodes. A complete summary of histopathological findings can be found in Appendix H.

Lung: Exposure-related findings in the lung of male and female rats were limited to infiltration cellular, histiocyte (increased numbers of alveolar macrophages in the alveoli) and pigmentation (presumed to be the test article). In contrast to micro-C_60_ no evidence of chronic active inflammation in the lung was found in nano-C_60_-exposed rats. The incidences of these lesions were statistically significant in high exposure females only (Table 6). In the males, infiltration cellular, histiocyte was seen in one control, in one 0.5 mg/m^3^ animal, and in three 2 mg/m^3^ animals. Severity was minimal in the control and 0.5 mg/m^3^ groups and was minimal to mild in the 2 mg/m^3^ group. In the females, infiltration cellular, histiocyte was seen in two control animals, in one 0.5 mg/m^3^ animal, and in eight of the 2 mg/m^3^ animals. The severity was minimal in all animals. Pigmentation was seen in eight females in the 2 mg/m^3^ group only, and the severity was mild. The lesions in both sexes were morphologically identical to the lung lesions seen in the rats exposed to micro-C_60_ particles.

Bronchial and mediastinal lymph nodes: Pigmentation was the only exposure-related finding in the bronchial and mediastinal lymph nodes (Table 6) and was seen in males and females. Pigmentation incidence in the bronchial lymph node was significantly increased in the 2 mg/m^3^ groups of males and females. In the mediastinal lymph node in males, the incidence of pigmentation was significantly increased only in the 0.5 mg/m^3^ group compared to the control group. In females, the incidences of pigmentation were statistically significant in the 0.5 and 2 mg/m^3^ groups. All instances of this lesion were of minimal severity. The lesions were morphologically identical to the lymph node lesions seen in the rats exposed to micro-C_60_ particles.

Other lesions: In the testes, three animals in the 2 mg/m^3^ group had degeneration of the germinal epithelium compared to none in the control and 0.5 mg/m^3^ groups (Table 6). Two of these animals also had hypospermia in the epididymis. The incidence was not statistically significant, and as a common background lesion in rats, the significance of this finding is unclear. The incidence of chronic progressive nephropathy was significantly increased in the 2 mg/m^3^ group compared to controls. The severity in all cases was minimal. Because this is a common background lesion in rats, especially males, the significance of this finding is unclear.

### Electron Microscopy

#### Micro-C_60_ Study

Transmission electron microscopy (TEM) was performed on formalin-fixed tissues from three male rats from the 30 mg/m^3^ group. The lung from two animals and the bronchial lymph node and liver from one animal each were examined. Electron-dense material consisting of agglomerations of rounded profiles consistent with C_60_ nanoparticles as described by Yamawaki and Iwai^85^ and Shinohara et al.^86^ were observed within macrophages in the lung (Figure 11 and Figure 12) and bronchial lymph node (Figure 13 and Figure 14). Similar material was not observed in other structures within the lung or bronchial lymph node or in the liver.

Figure 11

Transmission Electron Micrograph of an Alveolar Macrophage in the Lung of a Male Wistar Han Rat Exposed by Nose-only Inhalation to 2 mg/m3 Nano-C60 for Three Months (9900×)

Note the electron-dense material within the macrophage.

Figure 12

Transmission Electron Micrograph of an Alveolar Macrophage in the Lung of a Male Wistar Han Rat Exposed by Nose-only Inhalation to 2 mg/m3 Nano-C60 for Three Months (43,000×)

Higher magnification of Figure 11. The electron-dense material is consistent with the test article.

Figure 13

Transmission Electron Micrograph of a Macrophage in the Bronchial Lymph Node of a Male Wistar Han Rat Exposed to 30 mg/m^3^ Micro-C_60_ by Nose-only Inhalation for Three Months

Note the electron-dense material within the macrophage.

Figure 14

Transmission Electron Micrograph of a Macrophage in the Bronchial Lymph Node of a Male Wistar Han Rat Exposed by Nose-only Inhalation to 30 mg/m^3^ Micro-C_60_ for Three Months

Higher magnification of Figure 13. The electron-dense material is consistent with micro-C_60_ and appears identical to that seen in Figure 12.

#### Nano-C_60_ Study

TEM was performed on formalin-fixed lung tissue from one male rat exposed to 2 mg/m^3^ nano-C_60_ particles. The findings were identical to those described above for the lungs of the rats exposed to 30 mg/m^3^ micro-C_60_ particles.

### Immunotoxicity

#### BALF Cell Differentials

Changes were observed in the differential cell counts of BALF collected from female rats as part of the immunotoxicological evaluations. In general, cellularity of the BALF in the micro-C_60_ exposure groups was increased, particularly in the 15 and 30 mg/m^3^ groups. Changes in BALF in the nano-C_60_ exposed female rats was restricted to a small but statistically significant increase in lymphocytes in the 0.5 mg/m^3^ exposure group. The increased cellularity in the micro-C_60_ exposure groups was accompanied by an alteration in the cell types observed in the BALF (Table 7 and Table 8). For example, whereas the BALF of controls consisted almost exclusively (>99%) of macrophages (Figure 15A), the BALF differential of the 30 mg/m^3^ group included 81%, 16.5%, 2.2%, 0.3%, and 0.0% of macrophages, neutrophils, lymphocytes, eosinophils, and basophils, respectively, and would be consistent with the inflammatory process observed in the lung histopathological findings. Further, similar to the bronchoalveolar macrophages observed in the lung histopathology, macrophages of the BALF contained intracytoplasmic, brown to black, granular to globular pigment (presumptive test article) in the 2, 15, and 30 mg/m^3^ micro-C_60_ groups (Figure 15C).

Table 7 Bronchoalveolar Lavage Differential Results of Female Rats in the Three-month Nose-only Inhalation Study of Fullerene Micro-C_60_ (1 µm)^a^

| 0 mg/m^3^ | 2 mg/m^3^ | 15 mg/m^3^ | 30 mg/m^3^
Macrophages (%) | 99.7 ± 0.4 | 99.6 ± 0.2 | 98.5 ± 0.6 | 81.0 ± 3.7**^c^
Neutrophils (%) | 0.2 ± 0.2 | 0.2 ± 0.1 | 0.9 ± 0.4 | 16.5 ± 3.3**
Lymphocytes (%) | 0.2 ± 0.2 | 0.2 ± 0.1 | 0.6 ± 0.2* | 2.2 ± 0.8**
Eosinophils (%) | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.3 ± 0.2
Basophils (%) | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0

* Significantly different (p ≤ 0.05) from the control group by Shirley’s test; **p ≤ 0.01.

^a^ Data presented as mean ± standard error.

Table 8 Bronchoalveolar Lavage Differential Results of Female Rats in the Three-month Nose-only Inhalation Study of Fullerene Nano-C_60_ (50 nm)^a^

| 0 mg/m^3^ | 0.5 mg/m^3^ | 2 mg/m^3^
Macrophages (%) | 99.5 ± 0.1 | 98.1 ± 0.8 | 99.3 ± 0.06
Neutrophils (%) | 0.3 ± 0.01 | 1.4 ± 0.07 | 0.04 ± 0.01
Lymphocytes (%) | 0.0 ± 0.0 | 0.5 ± 0.2** | 0.2 ± 0.1
Eosinophils (%) | 0.1 ± 0.1 | 0.0 ± 0.0 | 0.1 ± 0.0
Basophils (%) | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0

* Significantly different (p ≤ 0.05) from the control group by Shirley’s test; **p ≤ 0.01.

^a^ Data presented as mean ± standard error.

Figure 15

Cell Morphology of Bronchoalveolar Lavage Fluid in Rats

(A) BALF cell morphology representative of control rats of both the nano- and micro-C_60_ studies; (B) Rat BALF cell morphology of the 2 mg/m^3^ nano-C_60_ consisting predominantly of macrophages containing variable amounts of granular to globular, brown to black intracytoplasmic granules (i.e., presumptive test article); (C) Rat BALF cell morphology of the 30 mg/m^3^ micro-C_60_ consisting predominantly of macrophages containing variable amounts of brown to black intracytoplasmic granules (i.e., presumptive test article).

BALF = bronchoalveolar lavage fluid. Note, increased numbers of neutrophils (arrows), many of which contain intracytoplasmic brown to black granules (arrowheads). Photomicrographs are of BALF cytospin preparations stained with a Romanowsky-type stain and examined microscopically (original magnification 40×).

Phenotyping also was performed on BALF cells from the additional immunotoxicity study female rats, and the data are presented in Table C-6. Rat BALF cells were dually stained with antibodies against ED2-like antigen CD163 and against CD11b. Quadrant analysis was conducted to calculate both the absolute number and percentage of BALF cells expressing one, both, or neither of the markers. Exposure to either particle size did not affect the total number of cells recovered from the BALF that ranged from 10–15 × 10^5^ cells.

In the micro-C_60_ study, a significant increase occurred in the absolute number (30 mg/m^3^, approximately 71%) and percentages (2 and 15 mg/m^3^, approximately 22%) of double-negative cells. These double-negative (i.e., CD163^−^CD11b^−^) rat BAFL cells in the present study consisted primarily of alveolar macrophages, in addition to a smaller population of other cell types, including T and B lymphocytes, NK cells, eosinophils, and mast cells. Compared to the control group, significantly lower absolute numbers (2 and 15 mg/m^3^, 98%) and percentages (all exposed groups, 95% to 98%) of double-positive cells were observed. The cells staining positive for both CD163 and CD11b were most likely a combination of resident airway macrophages. Rats exposed to 30 mg/m^3^ C_60_ had significant increases in both the absolute number (568%) and percentage (498%) of single-positive CD163^−^CD11b^+^ cells accompanied by significant positive trends. The cells staining positive for CD11b only (i.e., CD163^−^CD11b^+^) were neutrophils and other myeloid cells. The significant increases in the percentage and absolute numbers of CD163^−^CD11b^+^ neutrophils observed in rats exposed to 30 mg/m^3^ micro-C_60_, correlated with the significant increase in neutrophils in rats in the same exposure group identified by BAL fluid differential cell counting (Table 7).

In the nano-C_60_ study, absolute numbers (86% and 91%, respectively) and percentages (86% and 89%, respectively) of double-positive cells (resident airway macrophages) were significantly lower following exposure to 0.5 or 2 mg/m^3^ compared to the control group; significant negative trends in both absolute number and percentage also occurred (Table C-6).

#### Spleen Cell Phenotype

Results of the spleen cell phenotype analysis in female rats exposed to micro-C_60_ are presented in Table C-1. Surface markers used for spleen cell phenotyping were CD45^+^ B-cells, CD5^+^ T-cells, CD4^+^CD5^+^ helper T cells (T_H_), CD8^+^CD5^+^ cytotoxic T-cells, NK^+^CD8^+^ natural killer cells, and HIS6^+^ splenic macrophages. In the micro-C_60_ study, there was a slight, but significant, increase in HIS6^+^ splenic macrophages (absolute number and percentage) in rats exposed to 15 mg/m^3^ C_60_. In the nano-C_60_ study, there was a significantly decreasing trend in the number of CD4^+^CD5^+^ T_H_ cells (absolute number and percentage).

The functional humoral immune response was evaluated by analyzing the spleen IgM AFC response to sRBC (Table C-2). In the nano-C_60_ study, there was a significant increase in the total number of spleen cells in rats exposed to 2 mg/m^3^. A significant positive trend in spleen weight was also observed.

Cytokine levels in the BALF of rats are presented in Table C-7. In the micro-C_60_ study, exposure to 15 or 30 mg/m^3^ C_60_ induced significant increases in concentrated IL-1 levels; a significant increasing trend also was observed. The level of concentrated MCP-1 was increased in rats exposed to 30 mg/m^3^, and a significant positive trend was observed. A significant negative trend in levels of neat TNF-α was observed in rats, with significant decreases occurring following exposure to 15 or 30 mg/m^3^. In the nano-C_60_ study, a significant negative trend in the levels of concentrated TNF-α occurred, with exposure to 2 mg/m^3^ resulting in a significant decrease.

## Three-month Studies in Mice

### Tissue Burden

Tissue burden data for mice are presented in Appendix B. In the current studies, lung weights (g) and lung C_60_ concentrations (µg C_60_/g lung) were determined in male and female mice following the final exposure (day 89). In addition, lung burdens were assessed in male mice only 14, 28, and 56 days after exposure to assess lung clearance rates. Total C_60_ lung burden (µg C_60_/total lung) and exposure concentration-normalized lung burden (µg C_60_/lung per mg C_60_/m^3^) were calculated. Due to the increased lung weights in exposed mice, lung burdens, instead of concentrations in lung tissues, were used to calculate lung clearance rates.

In the micro-C_60_ studies, lung tissue weights were significantly increased at 0 days postexposure in females exposed to 30 mg/m^3^ C_60_ and at 0, 28 and 56 days postexposure in males exposed to 30 mg/m^3^ C_60_, relative to control animals (Table B-5). At lower concentrations, lung weights were significantly increased in males 56 days postexposure (15 mg/m^3^). In the nano-C_60_ studies, males exposed to 0.5 mg/m^3^ had significantly increased lung weights at all postexposure time points except day 0 (Table B-7). Males exposed to 2 mg/m^3^ had significantly increased lung weights 56 days postexposure.

Lung burden rapidly decreased at all postexposure time points in males exposed to all concentrations of the micro-C_60_ particles, with the exception of the groups exposed to 30 mg/m^3^ at 14 days (Table B-5). Clearance between postexposure days 0 and 14 was marginal in males exposed to 30 mg/m^3^, but following exposure day 14, lung burdens in this group decreased rapidly as well. Lung burdens rapidly decreased at all postexposure time points in males exposed to all concentrations of the nano-C_60_ particles (Table B-7).

There were no exposure concentration-related effects on normalized lung burdens in males or females exposed to the micro-C_60_ particles, although normalized lung burdens were slightly higher in males exposed to 30 mg/m^3^ at days 14, 28, and 56 postexposure compared to the 2 mg/m^3^ group (Table B-5). In the nano-C_60_ studies, normalized lung burdens were slightly higher at postexposure days 0 and 14 in males exposed 2 mg/m^3^, relative to those in the 0.5 mg/m^3^ group; the opposite effect occurred at postexposure days 28 and 56 (Table B-7).

Lung deposition and clearance parameters for males were calculated from C_60_ lung burden data (Table 9). The clearance rate constants (k) were comparable for both particle sizes at every exposure concentration except 30 mg/m^3^ (micro-C_60_), at which the clearance rate constant was approximately fourfold less. The calculated clearance half-life (t_1/2_) of both particles was generally unaffected by exposure concentration or particle size.

Table 9 Lung Deposition and Clearance Parameter Estimates for Male Mice Exposed to Fullerene C_60_^a^

Parameter | 0.5 mg/m^3^ | 2 mg/m^3^ | 15 mg/m^3^ | 30 mg/m^3^
Micro-C_60_ (1 µm)
A_0_ (µg fullerene C_60_/total lung) | | 37 | 204 | 615
k (days^−1^) | | 0.044 | 0.039 | 0.010
t_1/2_ (days) | | 16 | 18 | 68
α (µg fullerene C_60_/total lung per day) | | 2 | 8 | 11
A_e_ (µg fullerene C_60_/total lung) | | 38 | 211 | 1,038
Nano-C_60_ (50 nm)
A_0_ (µg fullerene C_60_/total lung) | 23 | 116
k (days^−1^) | 0.040 | 0.047
t_1/2_ (days) | 17 | 15
α (µg fullerene C_60_/total lung per day) | 0.9 | 5.5
A_e_ (µg fullerene C_60_/total lung) | 24 | 118

A_0_ = lung burden at t = 0 days postexposure; k = first-order lung clearance rate constant; t_1/2_ = lung clearance half-life; α = lung deposition rate; A_e_ = steady-state lung burden.

^a^ Data are presented as mean values.

Assuming first-order removal process, steady-state lung burdens are reached in approximately five half-lives. In the micro-C_60_ studies, the measured lung burdens in the 2 mg/m^3^ (38 µg C_60_/total lung; Table B-5) group were identical to the calculated steady-state lung burden for exposure to the same concentration (Table 9). Steady-state lung burdens were likely reached in males exposed to 2 or 15 mg/m^3^, but not 30 mg/m^3^. In the nano-C_60_ studies, the measured lung burden for exposure to 2 mg/m^3^ (115 µg C_60_/total lung; Table B-7) was almost identical to the calculated steady-state lung burden for exposure to the same concentration (118 µg C_60_/lung) (Table 9). Steady-state lung burdens were likely reached in males exposed to 2 mg/m^3^.

### General Toxicity

In the micro-C_60_ studies, all females survived to the end of the study (Table 10). One 2 mg/m^3^ male was euthanized moribund on day 63 of the study, however this was not considered to be related to exposure. Final mean body weights and mean body-weight gains of exposed groups of males and females were similar to those of the control groups (Table 10 and Figure 6). There were no exposure-related clinical findings in females throughout the study. The 2 mg/m^3^ male found moribund was lethargic with abnormal breathing, however these observations were not considered to be exposure-related. In the nano-C_60_ studies, all males and females survived to the end of the study (Table 11). Final mean body weights and mean body-weight gains of exposed groups of males and females were similar to those of the control groups (Table 11 and Figure 7). There were no exposure-related clinical findings in males or females.

Table 10 Survival and Body Weights of Mice in the Three-month Nose-only Inhalation Study of Fullerene Micro-C_60_ (1 µm)^a^

Concentration (mg/m^3^) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 10/10 | 20.6 ± 0.4 | 31.6 ± 0.7 | 11.0 ± 0.7
2 | 9/10^c^ | 20.9 ± 0.7 | 32.1 ± 0.9 | 11.6 ± 0.6 | 102
15 | 10/10 | 21.4 ± 0.4 | 30.9 ± 0.5 | 9.5 ± 0.7 | 98
30 | 10/10 | 21.2 ± 0.5 | 31.3 ± 0.7 | 10.1 ± 0.6 | 99
Female
0 | 10/10 | 17.5 ± 0.4 | 28.1 ± 0.6 | 10.6 ± 0.5
2 | 10/10 | 17.8 ± 0.2 | 28.4 ± 0.7 | 10.5 ± 0.7 | 101
15 | 10/10 | 17.7 ± 0.2 | 27.9 ± 0.5 | 10.2 ± 0.6 | 99
30 | 10/10 | 17.6 ± 0.2 | 28.6 ± 0.8 | 11.0 ± 0.9 | 102

^a^ Weights and weight changes are presented as mean ± standard error. Subsequent calculations are based on animals surviving to the end of the study. Differences from the control group are not significant by Dunnett’s test.

^b^ Number of animals surviving at 13 weeks/number initially in group.

^c^ Week of death: 9.

Figure 6

Growth Curves for Mice Exposed to Fullerene Micro-C_60_ (1 µm) by Nose-only Inhalation for Three Months

Table 11 Survival and Body Weights of Mice in the Three-month Nose-only Inhalation Study of Fullerene Nano-C_60_ (50 nm)^a^

Concentration (mg/m^3^) | Survival^b^ | Initial Body Weight (g) | Final Body Weight (g) | Change in Body Weight (g) | Final Weight Relative to Controls (%)
Male
0 | 10/10 | 21.3 ± 0.5 | 31.5 ± 0.8 | 10.2 ± 0.5
0.5 | 10/10 | 21.1 ± 0.8 | 31.7 ± 1.1 | 10.6 ± 0.7 | 101
2 | 10/10 | 21.0 ± 0.5 | 31.3 ± 0.6 | 10.3 ± 0.6 | 99
Female
0 | 10/10 | 17.6 ± 0.2 | 26.5 ± 0.5 | 8.9 ± 0.4
0.5 | 10/10 | 17.9 ± 0.3 | 27.9 ± 0.7 | 10.1 ± 0.6 | 105
2 | 10/10 | 18.3 ± 0.2 | 26.6 ± 0.4 | 8.3 ± 0.4 | 100

^a^ Weights and weight changes are presented as mean ± standard error. Differences from the control group are not significant by Dunnett’s test.

^b^ Number of animals surviving at 13 weeks/number initially in group.

Figure 7

Growth Curves for Mice Exposed to Fullerene Nano-C_60_ (50 nm) by Nose-only Inhalation for Three Months

Following exposure to micro-C_60_, absolute and relative lung weights of 30 mg/m^3^ females were significantly higher than those of the control group (Appendix H). There were no exposure-related changes in organ weights in males or females exposed to nano-C_60_ (Appendix H).

### Hematology

The summary hematology data for mice exposed to micro-C_60_ can be found in Appendix H. An apparent decrease in the erythron, evidenced by a minimally (≤3%) decreased red blood cell count, hemoglobin concentration, and automated instrument-derived hematocrit values, occurred in the 15 and 30 mg/m^3^ females, suggesting potential toxicological relevance. The manual spun hematocrit, however, did not corroborate the automated hematocrit. Additionally, no erythron effect occurred in the males (or in either males or females in the rat study.) Because the erythron changes were considered minimal (with results considered within biological limits), were inconsistent with the manual hematocrit values, and were not observed in male mice or in male or female rats, the toxicological relevance of this erythron finding is questionable.

The summary hematological data for mice exposed to nano-C_60_ can be found in Appendix H. The only finding of statistical significance was a minimal decrease in reticulocyte counts in males exposed to 0.5 or 2 mg/m^3^; this finding was not considered toxicologically significant.

### Reproductive Evaluations

Male mice exposed to micro-C_60_ displayed no changes in reproductive organ weights or sperm counts (Table A-3). Sperm motility was slightly lower in all exposed groups (72% to 78% compared to 83% in the controls). Males exposed to nano-C_60_ displayed no exposure-related changes in reproductive organ weights, sperm counts, or motility (Table A-6).

In the micro-C_60_ study, females exposed to 15 mg/m^3^ displayed an increased probability of extended estrus compared to controls (Table A-5). The time spent in any particular stage, however, was unaffected (Table A-4). In the nano-C_60_ study, females exposed to 0.5 or 2 mg/m^3^ displayed an increased probability of extended estrus, compared to controls (Table A-8). The time spent in any particular stage, however, was unaffected (Table A-7).

### Histopathology

#### Micro-C_60_ study

Exposure-related gross lesions were limited to brown discoloration of the lungs of all mice in the 30 mg/m^3^ groups, most mice in the 15 mg/m^3^ groups, and one male in the 2 mg/m^3^ group. Histologically, exposure-related lesions occurred in the lung, larynx, and bronchial lymph node. A complete summary of histopathological findings can be found in Appendix H.

Lung: Exposure-related findings in the lungs were limited to infiltration cellular, histiocyte (increased numbers of alveolar macrophages in the alveoli), chronic inflammation, and pigmentation (presumed to be the test article) (Table 12). The incidences of infiltration cellular, histiocyte, were statistically significant compared to controls in the 15 and 30 mg/m^3^ groups of males and females. The average severity increased with increasing exposure concentration.

Table 12 Incidences of Selected Nonneoplastic Lesions in Mice in the Three-month Nose-only Inhalation Study of Fullerene Micro-C_60_ (1 µm)

| 0 mg/m^3^ | 2 mg/m^3^ | 15 mg/m^3^ | 30 mg/m^3^
Male
Lymph Node, Bronchial^a^ | 6 | 4 | 5 | 9
Pigmentation^b^ | 2 (1.0)^c^ | 1 (1.0) | 2 (1.0) | 9* (2.9)
Larynx | 10 | 9 | 10 | 10
Metaplasia, squamous | 1 (1.0) | 0 | 5 (1.0) | 9** (1.1)
Lung | 10 | 10 | 10 | 10
Infiltration cellular, histiocyte | 0 | 0 | 10** (2.9) | 10** (3.9)
Inflammation, chronic active | 0 | 0 | 10** (1.0) | 10** (1.9)
Pigmentation | 0 | 0 | 10** (3.2) | 10** (3.8)
Female
Lymph Node, Bronchial | 5 | 6 | 5 | 6
Pigmentation | 2 (1.0) | 3 (1.0) | 1 (1.0) | 6 (2.7)
Larynx | 10 | 8 | 10 | 10
Metaplasia, squamous | 0 | 1 (1.0) | 6** (1.0) | 9** (1.2)
Lung | 10 | 10 | 10 | 10
Infiltration cellular, histiocyte | 0 | 0 | 10** (2.4) | 10** (4.0)
Inflammation, chronic active | 0 | 0 | 3 (1.0) | 10** (2.0)
Pigmentation | 0 | 0 | 10** (2.9) | 10** (4.0)

* Significantly different (p ≤ 0.05) from the control group by the Fisher exact test; **p ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

The incidences of chronic active inflammation were significantly increased in 15 and 30 mg/m^3^ males and in 30 mg/m^3^ females compared to the control groups. Chronic active inflammation was not present in lungs of male or female mice in control or 2 mg/m^3^ groups. The severity of inflammation increased with increasing exposure concentration. The incidences of pigmentation were significantly increased in 15 and 30 mg/m^3^ males and females; pigment was not seen in the control or 2 mg/m^3^ groups. The severity of the pigment increased with increasing exposure concentration. Lung lesions in mice were morphologically identical to lung lesions observed in rats exposed to micro-C_60_.

Larynx: Incidences of squamous metaplasia of the laryngeal epithelium were increased in the 15 and 30 mg/m^3^ males, compared to the control group, and the increase was significant in the 30 mg/m^3^ males (Table 12). Incidences of squamous metaplasia of the laryngeal epithelium were increased compared to controls, and the increases were significant in the 15 and 30 mg/m^3^ groups. Average severity was comparable in all groups. Squamous metaplasia of the laryngeal epithelium is characterized by a change from the normally single-layer cuboidal, ciliated epithelium to a flattened, multilayered, nonciliated epithelium. This lesion was observed at the base of the epiglottis.

Bronchial lymph node: The incidences of pigmentation were increased in the 30 mg/m^3^ males and females, and the increase in males was significant compared to controls; the severity of pigmentation was also increased. The lesions in mice were morphologically identical to the lymph node lesions in rats exposed to micro-C_60_ particles.

#### Nano-C_60_ Study

There were no exposure-related gross lesions in mice exposed to nano-C_60_ particles. Histologically, exposure-related lesions occurred in the lung and bronchial lymph nodes. A complete summary of histopathological findings can be found in Appendix H.

Lung: Incidences of infiltration cellular, histiocyte (increased numbers of alveolar macrophages in the alveoli), were significantly increased in the 2 mg/m^3^ males and slightly increased in 2 mg/m^3^ females compared to controls (Table 13). Incidences of pigmentation were significantly increased in the 2 mg/m^3^ males and females. One 2 mg/m^3^ male had chronic active inflammation, likely related to exposure to nano-C_60_ particles (no exposure-related inflammation occurred in the females). The lesions in mice were morphologically identical to the lung lesions observed in rats exposed to micro-C_60_ particles.

Table 13 Incidences of Selected Nonneoplastic Lesions in Mice in the Three-month Nose-only Inhalation Study of Fullerene Nano-C_60_ (50 nm)

| 0 mg/m^3^ | 0.5 mg/m^3^ | 2 mg/m^3^
Male
Lymph Node, Bronchial^a^ | 9 | 7 | 7
Pigmentation^b^ | 0 | 2 (1.0)^c^ | 5** (1.0)
Lung | 10 | 10 | 10
Infiltration cellular, histiocyte | 1 (1.0) | 2 (1.0) | 7** (2.3)
Inflammation, chronic active | 0 | 0 | 1 (1.0)
Pigmentation | 0 | 0 | 7** (2.9)
Female
Lymph Node, Bronchial | 10 | 7 | 10
Pigmentation | 2 (1.0) | 3 (1.0) | 4 (1.0)
Lung | 10 | 10 | 10
Infiltration cellular, histiocyte | 2 (1.5) | 1 (1.0) | 5 (1.0)
Pigmentation | 0 | 0 | 5* (2.4)

* Significantly different (p ≤ 0.05) from the control group by the Fisher exact test; **p ≤ 0.01.

^a^ Number of animals with tissue examined microscopically.

^b^ Number of animals with lesion.

^c^ Average severity grade of lesions in affected animals: 1 = minimal, 2 = mild, 3 = moderate, 4 = marked.

Bronchial lymph node: Incidences of pigmentation were increased in the 0.5 and 2 mg/m^3^ groups of males and females, compared to controls (Table 13), and the increase was significant in the 2 mg/m^3^ males. The severity was minimal in all groups. The lesions were morphologically identical to the lymph node lesions observed in rats exposed to micro-C_60_ particles.

### Immunotoxicity

#### BALF Cell Differentials

In general, cellularity of the BALF in the micro-C_60_ fullerene exposure groups was increased, particularly in the 15 and 30 mg/m^3^ animals. The increased cellularity was accompanied by an alteration in the cell types observed in the BALF (Table 14). For example, whereas the BALF of controls consisted almost exclusively (>99%) of macrophages (Figure 16A), the BALF differential of the 30 mg/m^3^ group changed to include 71.9%, 25.6%, 2.5%, 0.0%, and 0.0% of macrophages, neutrophils, lymphocytes, eosinophils, and basophils, respectively, which is consistent with the inflammatory process observed in the lung histopathological findings. Further, similar to the bronchoalveolar macrophages observed in the lung histopathology, macrophages of the BALF contained intracytoplasmic brown to black, granular to globular pigment (presumptive test article) in the 2, 15, and 30 mg/m^3^ groups (Figure 16C).

Table 14 Bronchoalveolar Lavage Differential Results of Female Mice in the Three-month Nose-only Inhalation Study of Fullerene Micro-C_60_ (1 µm)^a^

| 0 mg/m^3^ | 2 mg/m^3^ | 15 mg/m^3^ | 30 mg/m^3^
Macrophages (%) | 99.8 ± 0.2 | 99.8 ± 0.1 | 94.3 ± 1.1** | 71.9 ± 2.1**^c^
Neutrophils (%) | 0.0 ± 0.0 | 0.3 ± 0.1 | 5.6 ± 1.1** | 25.6 ± 2.0**
Lymphocytes (%) | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.1 ± 0.1* | 2.5 ± 0.5**
Eosinophils (%) | 0.2 ± 0.2 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0
Basophils (%) | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0

* Significantly different (p ≤ 0.05) from the control group by Shirley’s test; **p ≤ 0.01.

^a^ Data presented as mean ± standard error.

Figure 16

Cell Morphology of Bronchoalveolar Lavage Fluid in Mice

(A) BALF cell morphology representative of control mice of both the nano- and micro-C_60_ Studies; (B) Mouse BALF cell morphology of the 2 mg/m^3^ nano-C_60_ consisting predominantly of macrophages containing variable amounts of granular to globular, brown to black intracytoplasmic granules (i.e., presumptive test article); (C) Mouse BALF cell morphology of the 30 mg/m^3^ micro-C_60_ consisting predominantly of macrophages containing variable amounts of brown to black intracytoplasmic granules (i.e., presumptive test article).

BALF = bronchoalveolar lavage fluid. Note increased numbers of neutrophils (arrow), many of which contain intracytoplasmic brown to black granules (arrowhead). Photomicrographs are of BALF cytospin preparations stained with a Romanowsky-type stain and examined microscopically (original magnification 40×).

There were no statistically significant findings in the BALF differential cell counts of female mice exposed to nano-C_60_ (Table 15). Similar to the histopathological findings, however, bronchoalveolar macrophages from mice exposed to 0.5 or 2 mg/m^3^ nano-C_60_ fullerene often contained intracytoplasmic, brown to black, granular, to globular pigment.

Table 15 Bronchoalveolar Lavage Differential Results of Female Mice in the Three-month Nose-only Inhalation Study of Fullerene Nano-C_60_ (50 nm)^a^

| 0 mg/m^3^ | 0.5 mg/m^3^ | 2 mg/m^3^
Macrophages (%) | 99.8 ± 0.1 | 99.8 ± 0.1 | 99.7 ± 0.1
Neutrophils (%) | 0.2 ± 0.01 | 0.1 ± 0.0 | 0.1 ± 0.1
Lymphocytes (%) | 0.0 ± 0.0 | 0.1 ± 0.0 | 0.2 ± 0.1
Eosinophils (%) | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.1 ± 0.0
Basophils (%) | 0.0 ± 0.0 | 0.0 ± 0.0 | 0.0 ± 0.0

* Significantly different (p ≤ 0.05) from the control group by Shirley’s test; **p ≤ 0.01.

^a^ Data presented as mean ± standard error.

#### Spleen Cell Phenotype

Results of the spleen cell phenotype analysis in female mice are presented in Table C-1. In the micro-C_60_ studies, significantly fewer (approximately 22%) splenic macrophages (Mac-3^+^) were measured in mice exposed to 15 or 30 mg/m^3^, and a significant negative trend in cytotoxic T cells (T_CTL,_ CD4^−^CD8^+^) also occurred. The percentage of macrophages was significantly decreased in mice exposed to 30 mg/m^3^, which coincided with a significantly decreasing trend in the same animals. In the nano-C_60_ studies, significantly fewer absolute numbers of B cells (Ig^+^) (18% and 24%) were noted in mice exposed to 0.5 and 2 mg/m^3^, respectively, relative to controls; a significant negative trend also occurred. Significantly fewer total T cells (CD3^+^) (approximately 20%) also were observed in mice exposed to 0.5 mg/m^3^ relative to the control group; a significant negative trend in the percentage of B cells was also observed.

There were no effects on the number of IgM PFC/10^6^ splenocytes (specific activity) or PFC/spleen (total spleen activity) in the plaque assay in mice exposed to either micro- or nano-C_60_ particles. Serum levels of anti-sRBC IgM antibodies in mice were not affected by exposure to either size of C_60_ particles.

Spleen cells from exposed mice were cultured with and without anti-CD3 antibody to evaluate anti-CD3 antibody-mediated T cell proliferative response as a marker of cell-mediated immunity (Table C-3). There were no statistically significant changes in the basal proliferative response of spleen cells from mice exposed to the micro-C_60_ particles with the exception of mice in the 2 mg/m^3^ group, where a 47% decrease occurred in the basal proliferative response relative to control animals. There were no statistically significant changes in the basal proliferative response of spleen cells from mice exposed to the nano-C_60_ particles. There was an exposure-concentration-dependent decrease in the anti-CD3-stimulated proliferative response; however, the decrease did not reach statistical significance. The total number of spleen cells was significantly lower in mice exposed to 2 mg/m^3^; this coincided with a significant negative trend in the same animals.

In the micro-C_60_ study, a significant increase in MIP-1α occurred in female mice following exposure to 15 or 30 mg/m^3^ (Table C-7). In contrast, in the nano-C_60_ study there were no significant increases in MIP-1α in female mice following exposure up to 2 mg/m^3^.

## Genetic Toxicology

Micro-C_60_ particles, administered by nose-only inhalation for 3 months at concentrations of 2, 15, or 30 mg/m^3^ did not increase the frequencies of micronucleated reticulocytes (polychromatic erythrocytes) or erythrocytes (normochromatic erythrocytes) in peripheral blood of male or female rats or mice (Table D-1 and Table D-3). Similarly, nano-C_60_ particles administered by nose-only inhalation for 3 months at concentrations of 0.5 or 2 mg/m^3^ did not increase the frequencies of micronucleated reticulocytes or erythrocytes in peripheral blood of male or female rats or mice (Table D-2 and Table D-4). Neither size particle affected the percentage of reticulocytes in peripheral blood, suggesting no exposure-related bone marrow toxicity.