# Materials and Methods

## Procurement and Characterization of Bulk Fullerene C_60_

Fullerene C_60_ was obtained from SES Research (Houston, TX) in one lot (BT-6947). The study laboratory milled the test chemical in a ball mill to reduce particle size. After milling, initial purity and exposure testing revealed an insoluble impurity that was not present in the original unmilled material. The milled fullerene C_60_ was sent back to the manufacturer for repurification. The reprocessed fullerene C_60_ with the impurity removed (99.5% pure) was received from SES Research in one lot (BT-6947-Reprocess) that was used during the 3-month studies. Identity, purity, and moisture analyses were performed by the study laboratory at Battelle Toxicology Northwest [Richland, WA; high-performance liquid chromatography (HPLC) and gas chromatography (GC)] and by the analytical chemistry laboratories at Cyanta Analytical Services [Maryland Heights, MO; Fourier transform infrared (FTIR) spectroscopy, elemental analyses, and Karl Fisher titration], H & M Analytical Services, Inc. [Allentown, NJ; X-ray diffraction (XRD)], and Pacific Northwest National Laboratory (Richland, WA; laser Raman analysis) as described in Appendix E. Reports on analyses performed in support of the fullerene C_60_ studies are on file at the National Institute of Environmental Health Sciences.

The FTIR and laser Raman spectra of the test chemical were consistent with literature spectra (FTIR; Nakamoto and McKinney^65^), and the structure and composition of fullerene C_60_ XRD with Rietveld analysis showed only the face-centered cubic polymorph of fullerene C_60_.

The purity of the bulk chemical was determined by elemental analysis, GC, and HPLC. Elemental analyses showed a composition of 99.7% carbon, 0.24% nitrogen, less than 0.1% hydrogen, and less than 300 ppm sulfur. GC with flame ionization detection indicated one residual solvent, 1,2,4-trimethylbenzene (TMB), at approximately 0.8% (predrying) and 0.6% (postdrying). HPLC indicated an area percent purity of 98.5%. The overall purity of lot BT-6947-Reprocess was determined to be 98.5%. Karl Fischer titration indicated a water content of less than 0.09%.

To ensure stability, the bulk chemical was stored at room temperature in amber glass containers. Periodic reanalyses of the bulk chemical were performed during the 3-month studies by the study laboratory using HPLC, and no degradation of the bulk chemical was detected.

## Aerosol Generation and Exposure System for the Micro-C_60_ Studies

The aerosol generation and delivery system used a linear feed powder-metering device, particle attrition chamber, dispersion jet, and cyclone separator all located within a glove box in the exposure room (Figure 2). The air-driven shuttle bar in the powder-metering device dispersed the bulk material at timed intervals into a nitrogen gas stream; nitrogen gas was used to minimize oxidation of the test chemical during vaporization. The material suspended in the gas stream was further reduced in size by passing through the particle attrition chamber, which used a pressurized nitrogen stream to promote particle-to-particle impaction, breaking apart the particles. A high-pressure dispersion jet at the output of the particle attrition chamber added dispersion energy to drive the aerosol into the cyclone separator, which removed unwanted large particles from the aerosol stream. The aerosol stream from the glove box was directed to a residence chamber to allow for additional separation of larger particles by gravitational settling. The residence chamber was monitored to maintain generator output consistency using a real-time aerosol monitor (RAM), and material in excess of that required to maintain the exposure units at target concentrations was withdrawn through high-efficiency particulate air (HEPA) filters prior to delivery to the residence chamber. Aerosol was delivered from the residence chamber to each exposure carousel through a metering element that fixed the flow to each carousel. Humidified air was added to the aerosol-laden air downstream from the metering element to provide dilution and to humidify the airstream. Concentration was controlled by siphoning excess delivery flow from a point following the metering element but before the introduction of dilution air. Past the dilution air input, aerosol-laden air was directed to a computer-controlled pneumatic slide valve that served as the on-off control valve for the flow through a dedicated distribution system branch line to each exposure carousel.

Figure 2

Schematic of the Aerosol Generation and Delivery System in the Three-month Nose-only Inhalation Studies of Fullerene Micro-C_60_ (1 µm)

The rodent exposure carousel was developed by the study laboratory and consisted of stackable tiers with 16 nose-only exposure ports per tier. Each carousel consisted of five tiers, thus providing 80 ports for animal exposure. One end of the tube that served to restrain the individual animal was tapered to approximately fit the shape of the its head, and the diameter of the remaining cylindrical portion of the tube made it difficult for the animal to turn in the tube. The back portion of the tube was covered with a plastic cap, and tubes containing animals were fastened to the inhalation carousel by means of a bracket that ensured the nose portion of the tube protruded through a gasket and into the carousel.

The test aerosol entered the carousel through the top and then flowed radially to each of the 16 evenly spaced exposure ports per tier. Each port received approximately 500 mL/minute of exposure atmosphere, which equated to a total exposure unit inlet flow of 40 L/minute. Ports not used for animal exposure or sampling were closed off. This design provided uniform concentration and fresh test chemical to each animal connected to the exposure system and minimized any effect of the animals on the atmosphere because no exhaled air from one animal was able to reach the breathing zone of another. Each exposure carousel was surrounded by a temperature-controlled ventilated enclosure that minimized the release of aerosol from the carousel to the room and provided a means of cooling the animals confined to the nose tubes.

## Aerosol Generation and Exposure System for the Nano-C_60_ Studies

The aerosol generation and delivery system used the same glove box and residence chamber components as described for the micro-C_60_ studies (Figure 2). For the nano-C_60_ studies, however, the aerosol-laden airstream from the residence chamber was directed into four identically configured delta tubes designed to provide a metered flow in relation to the pressure drop maintained in the residence chamber (Figure 3). Downstream from each delta tube, a flowmeter-controlled siphon allowed for regulation of the flow into quartz tube furnaces present at a target of approximately 520°C for flash vaporization of the test article. Near the exit of each furnace tube, additional nitrogen gas was introduced into the flow to rapidly cool the vaporized test material, condensing it into nanometer-sized particles. The additional nitrogen also increased the velocity of the carrier stream, diluted the concentration of the particles, and reduced the opportunity for particle agglomeration. Humidified air was added to the aerosol-laden nitrogen gas stream that exited each furnace tube to provide additional dilution, cooling, humidification, and oxygenation to the exposure atmosphere.

Figure 3

Schematic of the Aerosol Generation and Delivery System in the Three-month Nose-only Inhalation Studies of Fullerene Nano-C_60_ (50 nm)

Subsequent aerosol flow through the computer-controlled pneumatic slide valves and exposure carousels was as described for the 1-µm studies, except that a second siphon and dilution air assembly was located just prior to the slide valves to reduce aerosol concentrations in the test atmosphere further. Exposure carousels for the nano-C_60_ studies provided 40 ports for animal exposure via 8 ports on each of the 5 tiers.

## Aerosol Concentration Monitoring for the Micro-C_60_ and Nano-C_60_ Studies

Summaries of the carousel aerosol concentrations are presented in Table E-1 and Table E-2. For the micro-C_60_ studies, micrometer-sized fullerene C_60_ aerosol was monitored for concentration using an online RAM. For the nano-C_60_ studies, nanometer-sized fullerene C_60_ was similarly monitored using a RAM-1 instrument. The analog output voltage from each RAM was recorded by the Battelle Exposure Data Acquisition and Control (BEDAC) software system and converted to mg/m^3^ exposure concentration by the application of a calibration curve. During the studies, if a measured concentration exceeded its allowed limits, the BEDAC program triggered an audible alarm or, in extreme cases, terminated the exposure.

RAM calibrations were performed by constructing response curves using RAM voltage recorded each day at the same time that duplicate atmosphere samples were collected from each exposure carousel on 25 mm Teflon^®^-coated glass-fiber filters; RAM voltages were corrected for zero-offset voltage measured in a HEPA-filtered airstream. Fullerene C_60_ collected on the filters from each exposure carousel was dissolved in a 50:50 mixture of TMB:toluene containing a known amount of internal standard and quantified using HPLC on an off-line chromatograph.

The off-line chromatograph was calibrated using gravimetrically prepared standard solutions of the test article and the internal standard in 50:50 TMB:toluene. These methods were demonstrated by the study laboratory to have adequate precision, accuracy, linear working range, day-to-day repeatability, and detection limits for measuring 1 µm and 50 nm fullerene C_60_ concentrations in the exposure carousels.

## Carousel Atmosphere Characterization for the Micro-C_60_ and Nano-C_60_ Studies

More comprehensive details and results of carousel atmosphere characterizations for both nano and micro-C_60_ are found in Appendix E

Aerosol particle size distribution was determined once prior to, and approximately monthly during, the micro-C_60_ studies by collecting aerosol samples from each exposure carousel (except the 0 mg/m^3^ carousels) using a Mercer style cascade impactor. Fullerene C_60_ was collected on stages one through seven within the impactor on 22 mm diameter stainless steel slides coated with silicone spray. The final, stage-eight sample was collected on a 25 mm diameter Pallflex^®^ Emfab™ glass-fiber filter. Collected aerosol was dissolved in a 50:50 mixture of TMB:toluene and assayed for mass of test material using HPLC. The relative mass collected on each stage was analyzed by the probit-based CASPACT impactor analysis program developed at the study laboratory^66^ to yield estimates of the mass median aerodynamic diameter (MMAD) of the particles.

The surface-area-to-mass ratio of micrometer-sized particles was estimated using data derived from the Mercer cascade impactor data and carousel mass concentrations. Mass median diameter (MMD) was calculated from MMAD using the Hatch-Choate relationships for log-normal distributions. Count median diameter (CMD) was calculated from MMD. The average surface area particle diameter (d_s_) and the average mass particle diameter (d_m_) were calculated from CMD, assuming a spherical particle shape. The surface area per particle was calculated from d_s_. The total number of particles per volume of air was calculated from d_m_ and the aerosol concentration determined from the RAM data. Once the total number of particles per volume of air was determined, the surface area per particle was multiplied by this value to obtain total surface area per volume of air. Total surface area per volume of air was divided by total mass per volume of air to obtain the ratio of total surface area to total mass. Estimates of particle sizes and surface-area-to-mass ratios during the micro-C_60_ studies are presented in Table E-3; MMAD values fell well below the 3.0 µm upper limit criterion required by the design of the studies.

For the nano-C_60_ studies, aerosol particle size distribution was initially measured without animals in the exposure carousels during prestart studies using a Model 125B NanoMOUDI™ Low Pressure Cascade Impactor. The NanoMOUDI™ classified particles according to aerodynamic size by inertial impaction in several multinozzle stages stacked in series. The chemically analyzed relative mass collected on each impactor stage was analyzed from a validated spreadsheet using the manufacturer’s values for impactor stage effective cutoff diameter. Data from this impactor resulted in a true measurement of MMAD for the aerosolized test article in each exposure carousel, but the device could not be used with animals in the exposure carousels because diversion of approximately half the aerosol flow to each carousel was required for proper functioning of the impactor. Accordingly, size distribution of the 50 nm particles was also measured using a Scanning Mobility Particle Sizer (SMPS™) that combined particle sizing by electrical mobility with condensation particle counting. The primary measurement output of the SMPS™ was particle CMD. MMD was calculated from measured CMD, and the associated geometric standard deviation (GSD) using Hatch-Choate relationships assuming log-normal aerosol size distribution, and then converted to MMAD assuming a particle density of 1.72 g/mL. By these means, a correlation was established between the results of NanoMOUDI™ impactor and SMPS™ analyses enabling the use of the SMPS™ during the animal exposures to provide estimates of particle size distribution.

Measurements of particle size during animal exposures were conducted daily during the nano-C_60_ studies using the SMPS™. Monthly averaged results for these measurements in each exposure carousel during the 3-month nano-C_60_ studies are presented in Table E-4 and demonstrate the particles delivered to each exposure unit were nanometer sized.

The surface-area-to-mass ratios of nanometer-sized particles in the nano-C_60_ studies were estimated using data derived from the SMPS™ CMD and carousel exposure concentration using the same calculations as described for the micrometer-sized particles; the results are presented in Table E-5.

Buildup and decay rates for carousel aerosol concentrations were not determined. For nose-only carousels, the time for the concentration to reach 90% of its stable final concentration after start of exposure is less than the resolving ability of the measurement instrumentation and is calculated to be less than 2 seconds.

Uniformity of the aerosol concentration in the inhalation exposure carousels without animals present was evaluated before the 3-month micro- and nano-C_60_ studies began. The aerosol concentration was measured using the online monitor with continuous monitoring from the input line. Measurements were taken from carousel exposure ports located on the top, middle, and bottom tiers of the carousel. For the micro-C_60_ studies, total port variability (TPV) for the three carousels ranged from 4.0% to 4.7% relative standard deviation (RSD), and for the nano-C_60_ studies, TPV for the four carousels ranged from 4.3% to 4.8% RSD.

Fullerene C_60_ was determined to be stable under the generation and exposure conditions used during the 3-month studies by analyses conducted before and during the 3-month studies by the study laboratory and the analytical chemistry laboratories. Samples were collected and analyzed from all exposure carousels and from the generator reservoir. During the 3-month studies, bulk fullerene C_60_ in the generator reservoir was refilled as needed, and the analysis sample was collected from the reservoir at the end of the day after it was placed in service. Analyses included HPLC for area percent purity, GC with mass spectrometry (MS) detection for determination of residual TMB (not performed on reservoir samples before the 3-month studies), inductively coupled plasma/atomic emission spectroscopy (ICP/AES) for elemental analysis, and XRD and laser Raman spectroscopy for characterization of the form of the test material.

Exposure atmosphere samples were collected from all rat and mouse carousels on 25 mm glass-fiber Teflon^®^-coated filters for HPLC and ICP/AES analyses, and on A/E glass-fiber filters for XRD and laser Raman analyses. Atmosphere samples for GC/MS analyses were collected on activated coconut charcoal sorbent tubes.

For area percent purity assessments, filters and generator reservoir samples were extracted with TMB:toluene (50:50). For determination of TMB as a residue of repurification of the bulk test material, the sorbent tubes and generator reservoir samples were extracted with carbon disulfide. For elemental analyses, samples were microwave-digested in concentrated HCl:HNO_3_ (2:1) containing indium as an internal standard, filtered through Teflon^®^-coated syringe filters, and analyzed for the concentration of 15 elements.

XRD with Rietveld analysis indicated that the principal crystalline phase in samples from the generator reservoir and exposure atmosphere samples from all carousels both before and during the 3-month micro- and nano-C_60_ studies in rats and mice was the disordered face-centered cubic form of fullerene C_60_. The XRD-determined purity of all generator reservoir and atmosphere samples exceeded 99.7% and 98%, respectively. Laser Raman assays concluded that all the elemental carbon in the samples was in the form of C_60_ fullerene. Using HPLC, average area percent purity for the generator reservoir samples exceeded 98% prior to and during all studies. Area percent purity for the atmosphere samples collected from all carousels prior to and during the micro-C_60_ studies exceeded 98%; similar measurements prior to and during the nano-C_60_ studies indicated an exposure atmosphere purity of 99% or greater. GC/MS detected 0.6% TMB in all reservoir samples collected during the 3-month studies. TMB concentrations in atmosphere samples ranged from 0.4% to 0.6% prior to and during the micro-C_60_ studies and from 0.6% to 2.5% prior to and during the nano-C_60_ studies. ICP/AES analyses showed no elemental contamination in either the generator reservoir or exposure atmosphere samples collected before or during each study.

## Animal Source

Male and female Wistar Han [Crl:WI(Han)] rats were obtained from Charles River Laboratory (Raleigh, NC), and male and female B6C3F1/N mice were obtained from the National Toxicology Program (NTP) colonies maintained at Taconic Biosciences (formerly Taconic Farms, Inc.) Germantown, NY.

## Animal Welfare

All NTP animal toxicity studies are conducted in accordance with Public Health Service Policy on Humane Care and Use of Animals. All animal studies were conducted in an animal facility accredited by AAALAC International. Studies were approved by the Battelle Toxicology Northwest Animal Care and Use Committee and conducted in accordance with all relevant NIH and NTP animal care and use policies and applicable federal, state, and local regulations and guidelines.

## Three-month Studies

On receipt, rats were 4 weeks old and mice were 4 to 5 weeks old. Animals were quarantined for 13 (rats) or 12 (mice) days and were 6 (rats) or 6 to 7 (mice) weeks old on the first day of the studies. Before the studies began, five male and five female rats and mice were randomly selected for parasite evaluation and gross observation for evidence of disease. The health of the animals was monitored during the studies according to the protocols of the NTP Sentinel Animal Program (Appendix G). All test results were negative.

Groups of 10 male and 10 female core study rats and mice were exposed to fullerene C_60_ via nose-only inhalation at concentrations of 0, 2, 15, or 30 mg/m^3^ (micro-C_60_ studies) or 0, 0.5, or 2 mg/m^3^ (nano-C_60_ studies), 3 hours per day, 5 days per week, for 13 weeks. Additional groups of 24 male rats and mice and 8 female rats and mice designated for tissue burden studies and groups of 16 female rats and mice designated for immunotoxicity studies were exposed to the same concentrations for 12 to 13 weeks. Prior to the initiation of the study, animals were placed in the nose-only restraint tubes for up to 2 hours per day for at least 3 days to acclimate to handling and the exposure system.

NTP historically has used only female rodents for immunotoxicology studies, as they tend to be more immunologically responsive than their male counterparts, which allows for the detection of subtle immunological effects. In addition, resource and operational constraints limited the number of animals that could be studied in the nose-only system, so pragmatic decisions were made to study both male and female mice for the core toxicity study but use only female mice for the immunotoxicity study arm and use male mice for the post-exposure clearance studies.

NTP-2000 feed and water were available ad libitum except during exposure periods. Rats and mice were housed individually. Core study animals were weighed initially, and body weights and clinical findings were recorded on day 3 (micro-C_60_ rats and mice) or 4 (nano-C_60_ rats and mice), weekly thereafter, and at the end of the studies. Details of the study design and animal maintenance are summarized in Table 1. Information on feed composition and contaminants is provided in Appendix F.

Table 1 Experimental Design and Materials and Methods in the Three-month Nose-only Inhalation Studies of Fullerene Micro-C_60_ (1 µm) and Nano-C_60_ (50 nm)

Study Design
Study Laboratory
Battelle Toxicology Northwest (Richland, WA)
Strain and Species
Wistar Han [Crl:WI(Han)] rats
B6C3F1/N mice
Animal Source
Rats: Charles River Laboratory (Raleigh, NC)
Mice: Taconic Farms, Inc. (Germantown, NY)
Time Held Before Studies
Rats: 13 days
Mice: 12 days
Average Age When Studies Began
Rats: 6 weeks
Mice: 6 to 7 weeks
Date of First Exposure
November 5, 2007
Duration of Exposure
3 hours per day, 5 days per week, for 13 weeks
Date of Last Exposure
1 µm rats and mice: January 31, 2008
50 nm rats and mice: February 1, 2008
Necropsy Dates
1 µm rats and mice: February 1, 2008
50 nm rats and mice: February 2, 2008
Average Age at Necropsy
Rats: 18 weeks
Mice: 19–20 weeks
Size of Study Groups
10 males and 10 females (core studies), 24 males and 8 females (tissue burden studies), or 16 females (immunotoxicity studies)
Method of Distribution
Animals were distributed randomly into groups of approximately equal initial mean body weights.
Animals per Cage
1
Method of Animal Identification
Tail tattoo
Diet
NTP-2000 irradiated wafers (Zeigler Brothers, Inc., Gardners, PA), available ad libitum (except during exposure periods); changed weekly
Water
Tap water (Richland, WA, municipal supply) via automatic watering system (Edstrom Industries, Waterford, WI); available ad libitum except during exposure periods
Cages
Polycarbonate solid bottom (Lab Products, Inc., Seaford, DE); changed and rotated weekly
Bedding
Heat-treated, irradiated, hardwood bedding (Sani-Chip^®^, PJ Murphy Forest Products, Montville, NJ); changed weekly
Room Air Supply Filters
Single HEPA; changed as needed (indicator light), new at study start
Racks
Stainless steel housing racks holding hanging cages (Lab Products, Inc., Seaford, DE); changed weekly
Room Environment
Temperature: 72° ± 3°F
Relative humidity: 50% ± 15%
Room fluorescent light: 12 hours/day
Chamber air changes: 10/hour
Exposure Tube Environment
Temperature: 75° ± 3°F
Relative humidity: 55% ± 15%
Inlet air flow: 18–22 liters/minute
Exposure Concentrations
0, 2, 15, and 30 mg/m^3^ (1 µm studies)
0, 0.5, and 2 mg/m^3^ (50 nm studies)
Type and Frequency of Observation
Observed twice daily. Animals were weighed initially, on day 3 (1 µm studies) or 4 (50 nm studies), weekly thereafter, and at the end of the studies; clinical findings were recorded on day 3 (1 µm studies) or 4 (50 nm studies), weekly thereafter, and at the end of the studies.
Method of Euthanasia
100% carbon dioxide
Necropsy
Necropsies were performed on all core study animals. Organs weighed were heart, right kidney, liver, lung, right testis, and thymus.
Clinical Pathology
Blood was collected from the retroorbital sinus (rats) or supraorbital sinus (mice) from core study animals at the end of the studies for hematology and clinical chemistry (rats). Hematology: hematocrit; packed cell volume; hemoglobin; hemolysis; erythrocyte, nucleated erythrocyte, reticulocyte, and platelet counts; Howell-Jolly bodies (mice); mean cell volume; mean cell hemoglobin; mean cell hemoglobin concentration; and leukocyte count and differentials Clinical chemistry: urea nitrogen, creatinine, glucose, total protein, albumin, globulin, cholesterol, triglyceride, alanine aminotransferase, alkaline phosphatase, creatine kinase, sorbitol dehydrogenase, and bile salts
Histopathology
Complete histopathology was performed on 0, 30 (micro-C_60_ studies), and 2 (nano-C_60_ studies) mg/m^3^ core study rats and mice and on those that died early. In addition to gross lesions and tissue masses, the following tissues were examined: adrenal gland, bone with marrow, brain, clitoral gland, esophagus, eyes, gallbladder (mice), Harderian gland, heart and aorta, large intestine (cecum, colon, rectum), small intestine (duodenum, jejunum, ileum), kidney, larynx, liver, lung and mainstem bronchi, lymph nodes (mandibular, mesenteric, bronchial, mediastinal), mammary gland, ovary, pancreas, parathyroid gland, pituitary gland, preputial gland, prostate gland, salivary gland, seminal vesicle, skin, spleen, stomach (forestomach and glandular), testis with epididymis, thymus, thyroid gland, trachea, urinary bladder, and uterus. In addition, the lung, bronchial and mediastinal lymph nodes, and testis with epididymis in the remaining exposure groups, the kidney and larynx in the micro-C_60_ study mice, and the kidney in the nano-C_60_ study rats were examined.
Sperm Motility and Vaginal Cytology
At the end of the studies, sperm samples were collected from male core study rats and mice for sperm motility evaluations. The following parameters were evaluated: spermatid heads per testis and per gram testis, motility, and sperm per cauda epididymis and per gram epididymis. The left cauda, left epididymis, and left testis were weighed. Vaginal samples were collected for up to 16 consecutive days prior to the end of the studies from core study female mice for vaginal cytology evaluations.
Tissue Burden
Liver, lungs, bronchial lymph nodes, and spleen were collected and analyzed for fullerene C_60_ concentrations from six male and eight female tissue burden animals per exposure group on the last exposure day, immediately postexposure. Lungs were collected from six male tissue burden animals per exposure group per time point and analyzed for fullerene C_60_ concentrations at 14, 28, and 56 days postexposure.
Immunotoxicity
At study termination, blood and spleens of cohort 1 animals (8 females per exposure concentration) and bronchoalveolar lavage fluid (BALF) and spleens of cohort 2 animals (8 females per exposure concentration) were collected for immunotoxicity evaluation. Cohort 1 animals were evaluated for antigen-specific antibody responses. Cohort 2 animals were assayed for splenocyte phenotyping, anti-CD3 mediated proliferation, natural killer cell activity, BALF cell differentials (rats), BALF cytokine levels, and mixed leukocyte response (mice).

The 3-month rat and mouse inhalation studies were designed on the basis of published data from preliminary 10-day nose-only inhalation studies,^11^ which were the first reported inhalation studies of fullerene C_60_. A high exposure concentration of 2 mg/m^3^ was selected for the nano-C_60_ studies because minimal toxicity was observed at that concentration in the Baker et al.^11^ studies and because generation of higher concentrations was not technically feasible. The subsequent exposure concentrations for the nano- and micro-C_60_ studies were selected to adequately compare across equivalent mass and equivalent surface area. The surface area (m^2^/g) of the 15 to 30 mg/m^3^ micro-C_60_ particles was approximately equivalent to the surface area of the 2 mg/m^3^ nano-C_60_ particles, allowing for comparison of equivalent surface area with different size particles. The lowest exposure concentration for the micro-C_60_ particles was 2 mg/m^3^ to allow comparison of equivalent masses of different size particles.

### Clinical Pathology

Animals were anesthetized with carbon dioxide, and blood was collected from the retroorbital plexus (rats) or supraorbital sinus (mice) of core study animals at the end of the studies for hematology and clinical chemistry (rats only) analyses. Blood samples for hematological analyses were placed in tubes containing potassium EDTA. Packed cell volume; hemoglobin concentration; erythrocyte, platelet, and leukocyte counts; mean cell volume; mean cell hemoglobin; and mean cell hemoglobin concentration were determined using an Abbott Cell-Dyn 3700 Analyzer (Abbott Diagnostics Systems, Abbott Park, IL). Manual hematocrit values were determined using a microcentrifuge (Heraeus haemofuge; Heraus Holding, GmbH, Hanau, Germany) and a Damon/IEC capillary reader (International Equipment Co., Needham Heights, MA) for comparison to Cell-Dyn values for packed cell volume. Blood smears were stained with Romanowsky-type aqueous stain in a Wescor 1720 aerospray slide stainer (Wescor, Inc., Logan, UT). Reticulocytes were stained with New Methylene Blue and enumerated as a reticulocyte:erythrocyte ratio using the Miller disc method.^67^ Blood samples for clinical chemistry analyses were placed in tubes containing a separator gel, allowed to clot, and centrifuged. Parameters were determined using a Roche Hitachi 912 System (Roche Diagnostic Corporation, Indianapolis, IN). Table 1 lists the parameters measured.

### Reproductive Evaluations

At the end of the 3-month studies, samples were collected for sperm motility and vaginal cytology evaluations on core study rats and mice according to NTP specifications.^68^ The parameters evaluated are listed in Table 1. For 16 consecutive days prior to scheduled terminal sacrifice, the vaginal vaults of the female mice were moistened with saline, if necessary, and samples of vaginal fluid and cells were stained. Relative numbers of leukocytes, nucleated epithelial cells, and large squamous epithelial cells were determined and used to ascertain estrous cycle stage (i.e., diestrus, proestrus, estrus, and metestrus). Male animals were evaluated for sperm count and motility. The left testis and left epididymis were isolated and weighed. The tail of the epididymis (cauda epididymis) was then removed from the epididymal body (corpus epididymis) and weighed. Test Yolk buffer (rats) or modified Tyrode’s buffer (mice) was applied to slides and a small incision was made at the distal border of the cauda epididymis.^68^ The sperm effluxing from the incision were dispersed in the buffer on the slides, and the numbers of motile and nonmotile spermatozoa were counted for five fields per slide by two observers. Following completion of sperm motility estimates, each left cauda epididymis was placed in buffered saline solution. Caudae were finely minced, and the tissue was incubated in the saline solution and then heat fixed at 65°C. Sperm density was then determined microscopically with the aid of a hemacytometer. To quantify spermatogenesis, the testicular spermatid head count was determined by removing the tunica albuginea and homogenizing the left testis in phosphate-buffered saline containing 10% dimethyl sulfoxide. Homogenization-resistant spermatid nuclei were counted using a hemacytometer.

### Tissue Burden

The liver, lungs, bronchial lymph nodes, and spleen were collected from six male and eight female tissue burden animals per exposure group immediately postexposure on the last exposure day, and lungs were collected from six male tissue burden animals per exposure group at 14, 28, and 56 days postexposure. Tissues were weighed and stored at −70°C until analysis. Tissues were placed in centrifuge tubes, magnesium perchlorate (0.1 M) was added, an internal standard (C_70_) was added, and the contents were mixed. The solution was centrifuged to separate the aqueous and organic layers, and an aliquot of the organic layer was removed, filtered, and analyzed for fullerene C_60_ concentration using HPLC with ultraviolet-visible detection.

### Immunotoxicity

Immunotoxicity study animals were divided into two cohorts of eight female rats and mice per exposure group. On day 74 (mice) or 81 (rats), cohort 1 animals were immunized by tail-vein injection with a T-dependent antigen [sheep erythrocytes (sRBC)]. On day 78 (mice) or 85 (rats), blood and spleens were collected from cohort 1 animals for evaluation of antigen specific antibody responses to sRBC by evaluating the antibody-forming cell (AFC) response (rats and mice) and serum anti-sRBC IgM antibody levels (mice). Cohort 2 animals were not immunized and were used in evaluating responses to the following immunotoxicological assays: splenocyte phenotyping, anti-CD3 mediated proliferation, natural killer (NK) cell activity, bronchoalveolar lavage fluid (BALF) cell differentials (rats), and BALF cytokine levels; mice were also assayed for mixed leukocyte response. On day 79 (mice) or 86 (rats), cohort 2 animals were euthanized and the lungs were lavaged twice with 1 (mice), 5 (50 nm rats), or 10 (micro-C_60_ rats) mL aliquots of Hank’s Balanced Salt Solution (HBSS) with 50 µg/mL gentamicin, a bacteriostatic antibiotic. The lavage fluid was centrifuged, and the cell pellet was separated from the fluid. The cell pellet was washed with 10 mL HBSS and centrifuged, the supernatant was discarded, and the cell pellet was resuspended in 1 mL HBSS. The spleen of each cohort 2 animal was removed and placed in individual collecting tubes containing Earl’s Balanced Salt Solution (EBSS) with 15 mM 4-(2-hydroxyethyl)-1-piperazineethanesulfonic acid (HEPES), supplemented with gentamicin. A wet weight was obtained for each individual spleen. The spleens and BALF cells were shipped in tubes on crushed ice to Virginia Commonwealth University (VCU) (Richmond, VA) for immunoassay evaluations on the following day. The collected serum and BALF samples were frozen and shipped separately on dry ice to VCU where they were maintained at −70°C until evaluated. Upon arrival at the VCU testing facility, single-cell spleen suspensions were prepared. Spleen cell suspensions for cohort 1 were centrifuged and resuspended in 6 mL (rats) or 3 mL (mice) of EBSS with 15 mM HEPES. Cell suspensions for cohort 2 were centrifuged and resuspended in Roswell Park Memorial Institute (RPMI) 1640 media supplemented with 10% fetal bovine serum. For cohort 2, spleen cells were resuspended in 6 mL (rats) or 3 mL (mice) of RPMI, and BALF cells were resuspended in 1 mL of RPMI. The parameters evaluated are listed in Table 1.

### Necropsy

Necropsies were performed on all core study animals. The heart, right kidney, liver, lung, right testis, and thymus were weighed. Tissues for microscopic examination were fixed and preserved in 10% neutral buffered formalin (except eyes were first fixed in Davidson’s solution, and testes, epididymides, and vaginal tunics were first fixed in modified Davidson’s solution), processed and trimmed, embedded in paraffin, sectioned to a thickness of 4 to 6 µm, and stained with hematoxylin and eosin. The lungs and trachea were infused with 10% neutral buffered formalin up to a normal inspiratory volume prior to fixation and processing. Complete histopathological examinations were performed by the study laboratory pathologist on all control, 30 mg/m^3^ (micro-C_60_ study) and 2 mg/m^3^ (nano-C_60_ study) animals. Histopathological evaluation of the lung and mainstem bronchi, bronchial and mediastinal lymph nodes, and testis with epididymis was performed in all exposure groups. Table 1 lists the tissues and organs routinely examined.

After a review of the laboratory reports and selected histopathological slides by a quality assessment (QA) pathologist, the findings and reviewed slides were submitted to an NTP Pathology Peer Review (PPR) coordinator for a second independent review. Any inconsistencies in the diagnoses made by the study laboratory and QA pathologists were resolved by the NTP PPR process. Final diagnoses for reviewed lesions represent a consensus of the PPR or a consensus among the study laboratory pathologist, NTP pathologist, QA pathologist(s), and the PPR coordinator. Details of these review procedures have been described, in part, by Maronpot and Boorman^69^ and Boorman et al.^70^

## Statistical Methods

### Calculation and Analysis of Lesion Incidences

The incidences of lesions are presented as the numbers of animals bearing such lesions at a specific anatomic site and the numbers of animals with that site examined microscopically. The Fisher exact test,^71^ a procedure based on the overall proportion of affected animals, was used to determine significance.

### Analysis of Continuous Variables

Two approaches were employed to assess the significance of pairwise comparisons between exposed and control groups in the analysis of continuous variables. Organ and body weight data, which historically have approximately normal distributions, were analyzed with the parametric multiple comparison procedures of Dunnett^72^ and Williams.^73,74^ Hematology, clinical chemistry, spermatid concentrations, epididymal spermatozoal measures, tissue burden, and immunotoxicity data, which have typically skewed distributions, were analyzed using the nonparametric multiple comparison methods of Shirley^75^ (as modified by Williams^76^) and Dunn.^77^ Jonckheere’s test^78^ was used to assess the significance of the dose-related trends and to determine whether a trend-sensitive test (Williams’ or Shirley’s test) was more appropriate for pairwise comparisons than a test that does not assume a monotonic dose-related trend (Dunnett’s or Dunn’s test). Prior to statistical analysis, extreme values identified by the outlier test of Dixon and Massey^79^ were examined by NTP personnel, and implausible values were eliminated from the analysis. Tests for extended periods of estrus, diestrus, metestrus, and proestrus, and skipped estrus and skipped diestrus, were constructed based on a Markov chain model proposed by Girard and Sager.^80^ For each exposure group, a transition probability matrix was estimated for transitions among the proestrus, estrus, metestrus, and diestrus stages, with provision for extended stays within each stage and for skipping estrus or diestrus within a cycle. Equality of transition matrices among exposure groups and between the control group and each exposed group was tested using chi-square statistics.

## Quality Assurance Methods

The 3-month studies were conducted in compliance with Food and Drug Administration Good Laboratory Practice Regulations.^81^ In addition, the 3-month study reports were audited retrospectively by an independent QA contractor against study records submitted to the NTP Archives. Separate audits covered completeness and accuracy of the pathology data, pathology specimens, final pathology tables, and a draft of this NTP Toxicity Study Report. Audit procedures and findings are presented in the audit reports and are on file at NIEHS. The audit findings were reviewed and assessed by NTP staff, and all comments were resolved or otherwise addressed during the preparation of this Toxicity Study Report.

## Genetic Toxicology – Peripheral Blood Micronucleus Test

Peripheral blood samples from male and female rats and mice were collected in tubes containing EDTA at the end of the 3-month studies and processed for flow cytometric evaluation of micronucleated reticulocytes (polychromatic erythrocytes; PCEs) and erythrocytes (normochromatic erythrocytes; NCEs) as described by Witt et al.^82^ Briefly, cells were fixed and labeled using a MicroFlow^PLUS^ Kit (Litron Laboratories, Rochester, NY) according to the manufacturer’s instructions. For each blood sample, 20,000 immature CD71^+^ reticulocytes and approximately 1 million mature erythrocytes were analyzed using a flow cytometer to determine the frequency of micronucleated cells of each type; in addition, the percentage of reticulocytes among the total erythrocytes was calculated as a measure of bone marrow toxicity.

Prior experience with the large number of cells scored using flow cytometric scoring techniques^83^ suggests assuming the proportion of micronucleated reticulocytes is approximately normally distributed is reasonable. The statistical tests selected for trend and for pairwise comparisons with the control group depend on whether the variances among the groups are equal. Levene’s test at α = 0.05 is used to test for equal variances. In the case of equal variances, linear regression is used to test for a linear trend with dose, and Williams’ test^73,74^ is used to test for pairwise differences between each treated group and the control group. In the case of unequal variances, Jonckheere’s test^78^ is used to test for linear trend, and Dunn’s test^77^ is used for pairwise comparisons of each treated group with the control group. Trend tests and pairwise comparisons with the controls are considered statistically significant if p ≤ 0.025. Ultimately, the scientific staff determined the final call after considering the results of statistical analyses, reproducibility of any effects observed, and the magnitude of effects.