# Introduction

Figure 1

Fullerene C_60_ (CASRN 99685-96-8; Chemical Formula: C_60_; Molecular Weight: 720.7)

Synonyms: Buckminsterfullerene; Buckminsterfullerene (C_60_); Buckyball, C_60_ fullerenecarbon (C_60_); carbon cluster (C_60_); carbon C_60_ fullerene; carbon (C_60_) mol.; carbon, mol. (C_60_); follene-60, footballene; footballene (C_60_); [60]fullerene; [5,6]fullerene C_60_; fullerene-60, fullerene-C_60_; fullerene C_60_ cluster; icosahedral C_60_; soccerballene

## Chemical and Physical Properties

Fullerene C_60_ (C_60_) is one of the primary allotropes of carbon; the others are graphite and diamond.^1^ C_60_ is a stable aggregate of 60 carbon atoms in the form of a truncated icosahedron with 60 vertices and 32 faces.^2,3^ C_60_ has a molecular weight of 720.66 g/mol, a melting point greater than 280 C, a relative density of 1.600 g/cm^3^ (at 20°C), and a log K_ow_ of 6.67.^4,5^

The diameter of single C_60_ particles is approximately 1 nanometer (nm), thereby classifying them as nanoscale materials.^6^ The European Union defines nanoscale materials as materials having at least one dimension between 1 and 100 nm.^7,8^ Like many other nanoscale materials, C_60_ molecules can aggregate into nanoscale or microscale particles.^7,9^ C_60_ can form a stable, colloidal nanocrystalline structure (nano-C_60_) in water at concentrations up to 100 μg/mL, in which the nano-C_60_ particles consist of faceted crystals varying in size from 50 to 300 nm.^9^

C_60_ is commercially available in a dry state in a highly aggregated crystalline form, and this crystal state can vary based on the degree of purity.^5^ At 98% purity, C_60_ exists as faceted, spherical particles ranging from 20 to 150 μm in diameter, with most particles falling in the range of 50 to 100 μm. At 99.5% purity, C_60_ exists as elongated particles ranging from 50 to 200 μm in length. These particles can be faceted or smooth and consist of 1 μm particles packed tightly together. At 99.9% purity, C_60_ exists as needle-like particles ranging from approximately 10 μm to approximately 1.5 mm in length and appearing as smaller, tightly bundled particles.^5,10^ C_60_ is hydrophobic, although water-soluble C_60_ suspensions have been created using solvents such as tetrahydrofuran, toluene, and dichlorobenzene.^11-13^

## Production, Use, and Human Exposure

Various methods are used to prepare C_60_, the most common being the pyrolysis of toluene, which produces a fullerene mixture that comprises C_60_ (60% to 70%), C_70_ (20% to 30%), and other higher order fullerenes. This mixture is then further purified into specific purities of C_60_ and C_70_.^14^

Industrial manufacturing in the United States produces an estimated 80 tons per year of engineered C_60_.^15^ Natural generation of C_60_ occurs following volcanic eruptions, forest fires, and the combustion of carbon-based materials, although the amount of C_60_ produced from natural or anthropogenic sources is currently unknown.^11,16,17^ The incidences of C_60_ in both ice-core samples and the fossil record suggest that C_60_ has existed in the environment throughout human history.^16,17^

Nanomaterials have many unique properties that make them ideal for use in a variety of products. Due to their small size, they often have chemical, biological, or physical properties that differ relative to the same material of a larger size; examples include higher strength, durability, and conductivity.^18-20^ These materials also have an increased surface-area-to-mass ratio, which, although ideal in some consumer applications, also means nanomaterials are more reactive; this increased reactivity makes nanomaterials more biologically active.^19,21^ Due to their small size, nanomaterials, including C_60_, have been investigated as drug delivery agents; however, there is concern for the materials accumulating in non-target tissues due to their ability to enter systemic circulation and pass through biological barriers such as the blood-brain barrier.^22^

C_60_ has been engineered for many uses and was once widely used in a variety of consumer applications including microelectronics, photovoltaics, batteries and fuel cells, and water treatment methods and as a drug delivery agent.^15,23,24^ Use of C_60_ in cosmetics products is steadily increasing as free radical scavenging properties of C_60_ are purported to be anti-aging.^25,26^ In 2014, the Food and Drug Administration (FDA) published guidance on the use of nanomaterials in cosmetic products, citing concerns that the size of nanomaterials allows for differential biological activity relative to the same material in larger size.^18^ Exposure to C_60_ in aerosolized cosmetics is of particular concern, as pulmonary exposure to C_60_ has been shown to induce respiratory toxicity.^11,27,28^

Human exposure to engineered C_60_ due to industrial applications could occur via inhalation, oral, dermal, or parenteral routes.^6^ C_60_ has been determined to be present in urban air samples, and human exposure to airborne C_60_ released from combustion sources and industrial processes occurs primarily via inhalation.^29^ Nano-C_60_ is stable in water, allowing for the possibility of this form of C_60_ to exist in aqueous environmental samples.^9^

## Regulatory Status

There are no workplace exposure limits for C_60_.

## Absorption, Distribution, Metabolism, and Excretion

### Experimental Animals

General factors known to affect the absorption and distribution of nanoparticles include particle size, shape, aggregation size, and dispersion pattern. Following inhalation exposure, well dispersed nanoparticles tend to deposit at the alveolar duct bifurcations and epithelial surfaces in the distal regions of the lung in rodents.^30,31^ Particle size is an important factor, as smaller particles tend to travel farther into the pulmonary interstitium.^32^ Once particles are in the lung, retention depends on dose and particle size, as smaller nanoparticles are retained longer, especially at higher doses.^33^

Clearance of nanoparticles from the lung can occur following phagocytosis of particles by alveolar macrophages and by removal from the respiratory tract via the mucociliary escalator. In addition, alveolar macrophages can remove particles from the lung via the tracheobronchial and pleural lymphatic systems.^34,35^ Particles can also be trapped in the mucous layer of the airways and subsequently be cleared from the lung via translocation, without the involvement of macrophages.

The deposition rate and half-life of micro- and nano-C_60_ particles were evaluated in male F344 rats exposed by nose-only inhalation for 10 days.^11^ Exposure to C_60_ nanoparticles (55 nm diameter) 3 hours per day at a concentration of 2.22 mg/m^3^ resulted in a 41% higher deposition rate and a 50% higher deposition fraction than exposure to C_60_ microparticles (0.93 μm diameter) 3 hours per day at a concentration of 2.35 mg/m^3^. The half-life of the C_60_ nanoparticles (26 days) was similar to that of the C_60_ microparticles (29 days).

The National Toxicology Program (NTP) investigated the disposition of C_60_ (suspended in toluene) following intratracheal (IT) instillation and intravenous (IV) administration of 1 or 5 mg C_60_ per kg body weight (mg/kg).^36^ Particle size distribution analysis indicated that the average size of the fullerene C_60_ aggregates in suspension was approximately 1 μm. Following IT instillation, C_60_ in the lung showed minimal clearance over the 168-hour observation period and showed a greater than dose-proportional increase over the dose range tested. C_60_ was not detected in extrapulmonary tissues. Following IV administration, C_60_ was rapidly eliminated from the blood and was undetectable after 0.5 hours. The highest tissue concentrations occurred in the liver, followed by the spleen, lung, and kidney. C_60_ was cleared slowly from the kidney and the lung with estimated half-lives of 24 and 139 hours, respectively. The liver concentration decreased minimally over time; more than 90% of the C_60_ present at 0.5 hours remained at 168 hours. C_60_ also was not detected in urine or feces. The maternal transfer of C_60_ was evaluated in pregnant Sprague Dawley rats injected intravenously via the tail vein on gestational day 15 or postnatal day 8 with radiolabeled solubilized C_60_.^37,38^ Radioactivity (as a percentage of the total injected) was measured in the liver (43%), spleen (4%), reproductive tract (3%), placenta (2%), and fetuses (0.87%) 24 hours postinjection. In lactating dams, radioactivity was measured 24 hours postexposure in the liver (35%), spleen (4%), reproductive tract (0.10% to 0.42%), mammary tissue (0.48% to 0.94%), and milk. Distribution to the gastrointestinal tract of pups increased between 24 (0.28%) and 48 (0.43%) hours postinjection.

### Humans

Studies on the absorption, distribution, metabolism, or excretion of C_60_ in humans were not identified in the available literature.

## Toxicity

### Experimental Animals

Limited studies have assessed C_60_ toxicity following inhalation exposure in animals. A comparative study to analyze the toxicity of nano- or microscale C_60_ particles exposed male F344 rats (Taconic) to C_60_ fullerene nanoparticles (2.22 mg/m^3^, 55 nm diameter) and microparticles (2.35 mg/m^3^, 0.93 μm diameter) for 3 hours/day for 10 consecutive days using a nose-only exposure system. This study indicated that exposure to C_60_ nanoparticles increased total bronchoalveolar fluid (BALF) protein concentrations relative to control rats without altering cytokine concentrations.^11^ Rats exposed to C_60_ microparticles had lower concentrations of the cytokines GRO/KC and IL-18 and higher concentrations of TNFα and IL-1β in the BALF than did the control groups.

DNA microarray analysis has been used to assess gene expression profiles in the lungs of male Wistar rats exposed to C_60_ nanoparticles (0.12 mg/m^3^, 96 nm diameter) via nose-only inhalation for 4 weeks (6 hours/day, 5 days/week).^28^ Upregulation of genes involved in apoptosis, oxidative stress, inflammation, and metalloendopeptidase activity occurred 3 days and 1 month after C_60_ exposure.

Intratracheal instillation of a water-soluble suspension of C_60_ (47 nm average particle size), at doses of 0.5–2 mg/kg, caused increased neutrophilia and upregulated levels of pro-inflammatory cytokines in the lungs of ICR male mice.^6,39^ However, a single intratracheal instillation of C_60_ aggregates (160 nm diameter) to male Crl:CD^®^(SD)IGS BR rats at doses ranging from 0.2 to 3 mg/kg induced limited pulmonary toxicity; the only effects observed were increased neutrophilia in the BALF 24 hours postexposure and increased lipid peroxidation 24 hours and 3 months postinstillation.^40^ No histopathological effects were observed in the lungs.

To study interactions between hydroxylated fullerene and crystalline α‐quartz, 0.2, 2 and 20 µg fullerenol (C_60_[OH]_20 ± 2_) was administered as an intratracheal bolus prior to intratracheal instillation of 50 µg quartz to female BALB/cJ mice. These data showed decreased levels of neutrophils and induced an anti-inflammatory response in the lungs of exposed animals, suggesting that surface modification of C_60_ particles can alter potential in vivo toxicity.^41^

Intraperitoneal exposure to C_60_ has been associated with renal and hepatotoxicity.^6^ Exposure to C_60_ (60 mg/kg per day) via intraperitoneal injection for 12 days caused increased absolute and relative weight of the spleen in female Japan Charles River Sprague Dawley rats.^42^ Swiss mice exposed to 100 mg/mL micro-C_60_ (up to 10 g/kg) via intraperitoneal injection had increased liver and spleen weights 14 days postexposure.^43^ Histopathological examination of livers and spleens from the exposed mice demonstrated accumulation of C_60_ in the liver, predominantly in the Kuppfer and perisinusoidal cells. Mice exposed to 2.5 g/kg C_60_ had increased relative liver and spleen weights 8 weeks postexposure, increased hypertrophy and hyperplasia of hepatic stellate cells, and increased hyperplasia of the spleen.

Intraperitoneal injection of aqueous C_60_ suspensions (developed without an organic solvent) to male Wistar rats at up to 2 g/kg caused no observable signs of acute or subacute toxicity and protected against hepatic oxidative stress.^12^ Toxicity has not been demonstrated for oral exposure to C_60_.^6^ Male and female Sprague–Dawley rats orally administered 2 g/kg fullerene, a mixture of C_60_ and C_70_, showed no signs of toxicity after 14 days of exposure.^44^ Chen et al.^42^ reported that oral administration of a single 50 mg/kg dose of polyalkylsulfonated C_60_ (water-soluble) to female Sprague-Dawley CD(Crl:CDR (SD)BR) rats was not toxic; rats administered the same dose for 12 days also showed no signs of toxicity. Male Wistar rats orally administered C_60_ in olive oil (0.8 mg/mL; 1.7 mg/kg) for 7 months survived approximately twice as long as control animals.^45^

Concern for nanomaterial-induced immunotoxicity derives from phagocytes (i.e., neutrophils, monocytes, macrophages, and dendritic cells) ability to take up nanomaterials, although few in vivo studies have analyzed the effects of exposure to C_60_ on the immune system.^46,47^ Female C57BL/6 mice exposed to 1.1 μg colloidal C_60_ aggregates (165 nm mean diameter) via intravenous injection had repressed delayed-type hypersensitivity responses to methyl bovine serum albumin.^48^ Intraperitoneal exposure (daily injection with 5 μg of nano-C_60_) of C57BL/6 mice to a range of H_2_O-soluble C_60_ aggregates (50 to 250 nm size) caused a decrease in splenocyte proliferation and an increase in nitric oxide production by splenocytes.^49^ BALB/c mice produced anti-C_60_ antibodies when immunized (three intraperitoneal doses) with C_60_ particles conjugated to bovine thyroglobulin and administered in Freund’s complete and incomplete adjuvants.^50^

### Humans

Studies on the effects of C_60_ exposure in humans were not identified in the available literature.

## Reproductive and Developmental Toxicity

### Experimental Animals

Intraperitoneal injection of pregnant Slc mice on gestation day 10 with C_60_ (25, 50, or 137 mg/kg) solubilized in poly(vinylpyrrolidone) (PVP) resulted in the death of all embryos at 137 mg/kg.^37,51^ C_60_ was present in the yolk sac of mice exposed to 50 mg/kg, and the heads and tails of 50% of the embryos from these mice were abnormal in shape.

Zebrafish (Danio rerio) embryos exposed to nano-C_60_ (a core of C_60_ coated with hydroxylated C_60_) (1.5 mg/L) for up to 96 hours delayed zebrafish embryo and larval development, decreased survival and hatching rates, and caused pericardial edema.^52^ There are no studies on zebrafish with pure C_60_.

### Humans

Studies on the developmental or reproductive toxicity of C_60_ in humans were not identified in the available literature.

## Carcinogenicity

### Experimental Animals

No 2-year carcinogenicity studies of C_60_ were identified in the available literature. Dimethylbenz[a]anthracene-initiated CD-1 mice dermally exposed to C_60_/C_70_ (1 mg/mL in benzene) for 24 weeks had no skin tumors, demonstrating that C_60_/C_70_ is not a skin tumor promoter.^53^ Intraperitoneal exposure to H_2_O-soluble C_60_ aggregates (50 to 250 nm size) caused an increase in tumor proliferation in C57BL/6 mice also inoculated with B61F10 melanoma cells.^49^

### Humans

Epidemiological studies of C_60_ in humans were not identified in the available literature.

## Genetic Toxicity

The genotoxicity of nanomaterials, including carbon black and fullerenes, has been reviewed by Roller.^54^ Most nanomaterials have shown genotoxic potential in vitro for some endpoints, particularly DNA damage measured by the comet assay. Results are not consistent across all studies, however, and attempts to correlate responses with the physical properties of the various nanomaterials have not revealed any clear association.

### Fullerenes

Positive results have been reported with an aqueous C_60_ suspension over a concentration range of 0.048 to 0.43 µg/mL in the absence of an exogenous metabolic activation system (S9 mix) in the Bacillus subtilis Rec-assay, which measures differential toxicity between repair competent and repair deficient strains of the bacterium.^55^ The average diameter of fullerene particles was 117 nm in aqueous solution, but in bacterial culture broth, particle size increased to an average of 320 nm, which may have limited the ability of bacteria to take up the particles. Therefore, the results reported in this assay could have represented minimal responses. In a second DNA damage/repair assay in bacteria, the umu test in Salmonella typhimurium strain TA1535/pSK1002, positive results were seen with an aqueous suspension of C_60_ (320 nm) at 0.43 µg/mL in the presence and absence of S9 mix.^55^ In standard bacterial gene mutation assays with fullerenes (concentration ranges extending to 5,000 µg/plate), no mutagenicity was observed in any of several strains of S. typhimurium or Escherichia coli WP2uvrA/pKM101, with or without S9 mix.^44,56^ The dispersants used in these bacterial mutagenicity assays and particle sizes were 0.1% carboxymethylcellulose sodium (CMC-Na) with a C_60_ average diameter of 53 nm^56^ and dimethylsulfoxide with a mixture of C_60_ and C_70_ fullerite particles, not further characterized.^44^

Mixed results were also reported in chromosome damage assays in vitro with C_60_, with negative results reported in Chinese hamster CHL/IU cells for chromosomal aberrations, with and without S9,^44,56^ and positive results reported for micronucleus induction (a biomarker of chromosomal damage) in human A549 cells.^57^ In the micronucleus test, A549 cells were exposed to fullerenes (0.7 nm; suspended in physiological saline with 0.05% Tween 80) in the absence of S9 only, and a clear, dose-related increase in the frequency of micronucleated cells was seen over a concentration range of 0.02 to 200 µg/mL (0.003 to 34 µg/cm^2^). In the chromosomal damage assay reported by Shinohara et al.,^56^ particle size was approximately 57 nm and a 0.1% CMC-Na dispersant was used; the highest concentration tested, 100 µg/mL with or without S9, was limited by precipitation of the nanoparticle suspension.

In contrast to the positive in vitro micronucleus test results reported by Totsuka et al.,^57^ results of an in vivo bone marrow micronucleus test in male ICR mice treated with 88 mg/kg fullerenes (34 nm diameter, dispersed in 0.1% Tween 80) by gavage twice at 24-hour intervals were negative.^56^

Results of an in vitro comet assay for assessing DNA damage conducted in primary BALB/c mouse embryonic fibroblasts (FE1 MutaMouse™) treated with 100 µg/mL fullerenes (average particle size in media of 311 nm) for 3 hours were positive for oxidized purines and negative for DNA strand breaks.^58^ Results reported from in vivo DNA damage studies with fullerenes are mixed. Totsuka et al.^57^ reported increased levels of DNA damage, measured by the comet assay, in lung cells of male C57BL/6J mice treated with 0.2 mg fullerenes (0.7 nm diameter; suspended in saline/0.05% Tween 80) by intratracheal instillation and evaluated 3 hours after treatment, although some of the protocol details reported by these authors were inconsistent. Results of a second comet assay in lung cells of male Crl:CD9SD rats, dosed by intratracheal instillation with up to 2.5 mg/kg fullerenes (mean diameter 33 nm; suspended in 0.1% Tween 80 aqueous solution) one time or 0.5 mg/kg once weekly for 5 weeks, and killed 3 or 24 hours after final treatment, were negative.^59^ Consistent with these results, negative results were also reported in a comet assay that assessed DNA damage in bronchoalveolar lavage cells of ApoE^−/−^ mice given a single treatment of fullerenes average diameter of 122 to 164 nm; 54 µg/mouse) by intratracheal instillation and examined 3 hours later.^60^ In F344 rats, high-performance liquid chromatography (HPLC) revealed DNA damage in the form of 8-oxo-7-8-dihydro-2′-deoxyguanosine (8-oxodG) adducts in lung and liver cells of males 24 hours after administration of fullerenes (0.7 nm; 0.064 or 0.64 mg/kg) by single gavage; no increases in DNA adducts were seen in colon cells of these rats.^61^ Consistent with the increases in DNA adducts observed in lung tissue in the F344 rats, gpt mutant frequencies were reported to be significantly increased in lung tissues of C57BL/6J mice treated with 1 or 4 intratracheal instillations of fullerenes (0.7 nm; 0.2 mg/mouse) and sampled 8 to 12 weeks following treatment.^57^

### Modified Fullerenes

One laboratory investigated the genetic toxicity of water soluble polymer-enwrapped fullerenes (PVP/fullerenes), using the bacterial gene mutation and in vitro mammalian cell chromosomal aberrations assays, both with and without exogenous metabolic activation.^62^ No increases in mutations or cytotoxicity were seen in any of several strains of bacteria treated with up to 5,000 µg/plate of PVP/fullerenes. No increases in chromosomal aberrations were observed in Chinese hamster lung cells exposed for 6 or 24 hours to concentrations of PVP/fullerenes ranging from 1,000 to 5,000 µg/mL.

## Study Rationale

Nanometer-scale (nanoscale) and micrometer-scale (microscale) fullerene C_60_ were evaluated as part of an extensive assessment of nanomaterials under the National Toxicology Program’s Nanotechnology Safety Initiative. Nanomaterials were initially nominated by the Rice University Center for Biological and Environmental Nanotechnology due to their widespread use in a variety of commercial applications and inadequate information on possible biological interactions and toxicity following exposure. To evaluate the potential for differential effects based on particle size, two C_60_ fullerene aggregate sizes, 50 nm diameter (nano-C_60_) and 1 µm diameter (micro-C_60_), were selected for toxicity and tissue burden studies. Because inhalation is a primary route of exposure and inhalation toxicity data are limited, 3-month inhalation studies were conducted to assess the effects of nano-C_60_ and micro-C_60_ on pulmonary toxicity, tissue burden, and immunotoxicity, as well as general toxicity effects, in male and female Wister Han rats and B6C3F1/N mice.

The work presented here is a complete assessment of the toxicity of micro- (1 µm) and nano- (50 nm) fullerene C_60_ particles. Some of the tissue burden, respiratory toxicity, and immunotoxicity data from this work been published previously.^63,64^