# Appendix H Supplemental Data

Tables with supplemental data can be found here: https://doi.org/10.22427/NTP-DATA-TOX-87.

## H.1 Three-month 50 Nanometers Study Tables in Rats

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E05 – Clinical Observations Summary

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Sites (Systemic Lesions Abridged)

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P14 – Individual Animal Pathology Data

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P40 – Survival Curves

## H.2 Three-month 50 Nanometers Individual Animal Data in Rats

Female Individual Animal Body Weight Data

Female Individual Animal Clinical Observations

Female Individual Animal Non-Neoplastic Pathology Data

Female Individual Animal Organ Weight Data

Female Individual Animal Survival Data

Male Individual Animal Body Weight Data

Male Individual Animal Clinical Observations

Male Individual Animal Non-Neoplastic Pathology Data

Male Individual Animal Organ Weight Data

Male Individual Animal Survival Data

## H.3 Three-month 50 Nanometers Study Tables in Mice

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E05 – Clinical Observations Summary

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Sites (Systemic Lesions Abridged)

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P14 – Individual Animal Pathology Data

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P40 – Survival Curves

## H.4 Three-month 50 Nanometers Individual Animal Data in Mice

Female Individual Animal Body Weight Data

Female Individual Animal Non-Neoplastic Pathology Data

Female Individual Animal Organ Weight Data

Female Individual Animal Survival Data

Male Individual Animal Body Weight Data

Male Individual Animal Clinical Observations

Male Individual Animal Non-Neoplastic Pathology Data

Male Individual Animal Organ Weight Data

Male Individual Animal Survival Data

## H.5 Three-month 1.0 Micron Study Tables in Rats

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E05 – Clinical Observations Summary

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Sites (Systemic Lesions Abridged)

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P14 – Individual Animal Pathology Data

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P40 – Survival Curves

## H.6 Three-month 1.0 Individual Animal Data in Rats

Female Individual Animal Body Weight Data

Female Individual Animal Clinical Observations

Female Individual Animal Non-Neoplastic Pathology Data

Female Individual Animal Organ Weight Data

Female Individual Animal Survival Data

Male Individual Animal Body Weight Data

Male Individual Animal Non-Neoplastic Pathology Data

Male Individual Animal Organ Weight Data

Male Individual Animal Survival Data

## H.7 Three-month 1.0 Micron Study Tables in Mice

E03 – Growth Curves

E04 – Mean Body Weights and Survival Table

E05 – Clinical Observations Summary

P03 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site

P04 – Neoplasms by Individual Animal

P05 – Incidence Rates of Neoplasms by Anatomic Sites (Systemic Lesions Abridged)

P09 – Non-Neoplastic Lesions by Individual Animal

P10 – Statistical Analysis of Non-Neoplastic Lesions

P14 – Individual Animal Pathology Data

P18 – Incidence Rates of Non-Neoplastic Lesions by Anatomic Site with Average Severity Grades

P40 – Survival Curves

## H.8 Three-month 1.0 Micron Individual Animal Data in Mice

Female Individual Animal Body Weight Data

Female Individual Animal Non-Neoplastic Pathology Data

Female Individual Animal Organ Weight Data

Female Individual Animal Survival Data

Male Individual Animal Body Weight Data

Male Individual Animal Clinical Observations

Male Individual Animal Neoplastic Pathology Data

Male Individual Animal Non-Neoplastic Pathology Data

Male Individual Animal Organ Weight Data

Male Individual Animal Survival Data