# Appendix G Sentinel Animal Program

## G.1 Methods

Rodents used in the National Toxicology Program are produced in optimally clean facilities to eliminate potential pathogens that might affect study results. The Sentinel Animal Program is part of the periodic monitoring of animal health that occurs during the toxicological evaluation of test compounds. Under this program, the disease state of the rodents is monitored via sera or feces from extra (sentinel) or dosed animals in the study rooms. The sentinel animals and the study animals are subject to identical environmental conditions. Furthermore, the sentinel animals are from the same production source and weanling groups as the animals used for the studies of test compounds.

In these toxicity studies of fullerene C_60_ administered by nose-only inhalation for 3 months to Wistar Han [Crl:WI (Han)] rats and B6C3F1/N mice, blood samples were collected from the sentinel animals and allowed to clot and the serum was separated. All samples were processed appropriately with serology testing performed in house or sent to IDEXX BioResearch (formerly Research Animal Diagnostic Laboratory [RADIL], University of Missouri), Columbia, MO for determination of the presence of pathogens. The laboratory methods and agents for which testing was performed are tabulated below; the times at which samples were collected during the studies are also listed.

Blood was collected from five animals per sex per time point.

Table G-1 Laboratory Methods and Agents Tested for in the Sentinel Animal Program

Method and Test | Time of Collection
Rats
ELISA (in house)
Mycoplasma pulmonis | 3 weeks postarrival
Pneumonia virus of mice (PVM) | 3 weeks postarrival
Rat coronavirus/sialodacryoadenitis virus (RCV/SDA) | 3 weeks postarrival
Rat parvovirus (RPV) | 3 weeks postarrival
Sendai | 3 weeks postarrival
Multiplex Fluorescent Immunoassay (RADIL)
Kilham rat virus (KRV) | Study termination
M. pulmonis | Study termination
Parvo NS-1 | Study termination
PVM | Study termination
RCV/SDA | Study termination
Rat minute virus (RMV) | Study termination
RPV | Study termination
Rat theilovirus (RTV) | Study termination
Sendai | Study termination
Theiler’s murine encephalomyelitis virus (TMEV GDVII) | Study termination
Toolan’s H-1 virus | Study termination
Mice
ELISA (in house) | 3 weeks postarrival
Mouse hepatitis virus (MHV) | 3 weeks postarrival
Mouse parvovirus (MPV) | 3 weeks postarrival
M. pulmonis | 3 weeks postarrival
PVM | 3 weeks postarrival
Sendai | 3 weeks postarrival
TMEV | 3 weeks postarrival
Multiplex Fluorescent Immunoassay (RADIL)
Ectromelia virus | Study termination
Episodic diarrhea of infant mice (EDIM) | Study termination
Lymphocytic choriomeningitis virus (LCMV) | Study termination
M. pulmonis | Study termination
MHV | Study termination
Mouse norovirus (MNV) | Study termination
Parvo NS-1 | Study termination
MPV | Study termination
Minute virus of mice (MVM) | Study termination
PVM | Study termination
Reovirus | Study termination
TMEV GDVII | Study termination
Sendai | Study termination

## G.2 Results

All test results were negative.